# Appendix A Review of Interoperability and Data Standards

Interoperability can be broadly described as the capability to work together. Critical to it is the ability exchange information in a predictable, reliable way that ensures the fidelity of the information. In the context of healthcare, it is intended to allow information to be communicated beyond a single device, application, or vendor. If you use an electronic health record (EHR) system, you might be accustomed to sending a specimen out for processing by a lab vendor or even submitting a claim to a payer. The ability to do that and more is possible because there is an agreement on the standards for how data can be represented and communicated so that systems can interoperate.

Interoperability provides a whole host of additional benefits and opportunities, including:

- Improvements to medical reference, decision support, and automated quality reporting
  ○ Online reference and complex automation and alerting for clinical decision support, allergy evaluation, and drug-drug interaction checks are made easier. These can be targeted to a specific practice and patient population.
  ○ Data can be harvested and used for automated electronic clinical quality reporting.
- Addressing fragmented care
  ○ Sections of patient data live in multiple systems and organizations but that leads to incomplete information spread around in “pockets,” each only portraying one part of the story. Systems should be able to network – just like they do in other areas of business – so they may seamlessly and safely share data to make sure a patient’s comprehensive health history is available when they receive care.
- New ways to for patients to engage physicians and participate in their own care
  ○ Patient portals and mobile applications let patients access your health record on demand.
  ○ Data feeds from smart watches or other mobile health tools can give better insights into behavior that impacts patient health. In the age of “The Internet of Things,” the modern EHR should be able to incorporate more of that data. A smart watch can help profile heart rates and communicate that information to a provider, who might call a patient and ask them to come for a visit. This can promote proactive preventive care.
- Broadened insights and analytics
  ○ Patient data can also be federated through a central hub called a registry. A registry serves to collect and broker your data so multiple facilities can “pull” that data from the central hub. These registries, in turn, can act to “push” key elements back out to health practices you visit as they are updated in the hub.
  ○ The use of registries also introduces the possibility of integrating analytics into population health. With that information, you can endeavor to better treat specific populations who might be challenged by health issues such as diabetes, cardiovascular disease, or cancer, which are more prominent in their given community. Analysts can look for patterns and trends that may help improve health through additional care facilities or education via community outreach.
  ○ Real-time monitoring of symptoms (syndromic surveillance) in the event of an outbreak of flu or some other highly communicable disease.
  ○ Clinical quality and operations reporting is also improved as providers can more reliably identify challenges and determine if patients are receiving adequate, cost-effective care.
  ○ Access to richer patient data allows researchers to collaborate, just like they would for quality and operations reporting, but for the purposes of evaluating areas of concern and opportunity for specific patient populations. Data is the fuel that powers research and in its absence progress stutters and stops. When there is data, it is often in a variety of non-compatible formats that slow its use to a trickle. Being able to identify new treatments or evaluate the impacts of existing ones is what drives progress and improves lives.

We are just at the cusp of an electronic healthcare revolution. The ability to extract, communicate, and utilize data are foundational for its success and that success relies heavily on interoperability.

## Components of Interoperability

As EHRs emerged in the 1960s, 70s, and 80s, they promised a future that took them beyond being simply a word processor to capture a block of text. They provided new ways of discretely capturing problems, allergies, medications, labs, and a whole host of other facts which could be used to help drive care. These worked well when organizations used one and only one system but struggled when teams needed to exchange data between sites or even integrate new with a new system at the same site. Imagine you needed to transfer a patient and want to send their high-level information for continuity of care. When you hit “send” to communicate that data from one EHR to another, what is in the message and how is it sent? How can you be sure the receiving system was able to correctly interpret the associated diagnoses, medication, and procedures?

As computers and medical records systems started hitting their stride in the 1980s the pressure to allow for more seamless and faithful communication of data increased. There was recognition that to promote improved care, organizations needed to be able to integrate specialized components and tailor them to suit. Groups of like-minded physicians, informaticians, and technologists teamed up or formed entities dedicated to creating and promoting industry standards for representation and exchange of medical data. They worked to establish a variety of standards which could be used to ensure faithful communication of critical data.

Interoperability has three primary features:

- Semantic: The meaning of each piece of data - the nouns, verbs, and adjectives. Having common definitions to communicate concepts like diagnoses, procedures, laboratory tests, results, and other like notions are critical in communicating meaning.
- Syntactic: The structure and process of communication - the grammar. There needs to be agreement on how a computer-to-computer message and its contents should be communicated.
- Policy: Governance of the allowable use and methods of interacting with systems and data are defined and agreed-upon. There need to be defined policies that “legislate” the safe, accurate exchange of your data across organizational and even national boundaries.

### Semantic Interoperability

When data are recorded in or communicated between medical records systems, there is an assumption that a given medical concept is portable. When you record a specific medication, diagnosis, or result, in one system it would seem to be natural that the information be retrievable in another and retain the intended meaning. If a patient has their data recorded in their primary care provider’s E HR, they should be able to be referred to a specialist who has access to that same data and can review it in their own EHR.

In practice, this has been a difficult proposition. Allowing for communication between one medical record system and another is highly complex. Most systems record and store data in their own native, proprietary formats. Each is effectively an isolated container – an island. To exchange data between two systems, each must translate between the sender and receiver of the communication.

Each specific domain of information like laboratory data, pharmacology information, etc. can be very complex and require specialized knowledge. For a large academic medical center with potentially hundreds of systems that is a great deal of coordination and management. If you attempt to integrate that information on a system-by-system basis, the result will be extremely complex and require constant ongoing support as each system changes.

What we need is standardized semantic interoperability. A simple way to describe semantic interoperability is: “Say the same thing, mean the same thing.” When a discrete fact is stored within an electronic medical record system, it is most typically represented in some codified form that is intended to help reduce this potential confusion. This codified form represents a concept and all of its attributes. When you enter diagnosis, record an active medication, or order a lab, the human-readable description you see on the front-end of the EHR is probably not what is recorded on the computer. Instead, that order for a “glucose lab test” you see on screen is stored as something like “123ABC,” a coded value that means “glucose lab test.” The phrase “glucose lab test” is not what is typically recorded on the chart itself.

Exhibit 54 Visual Example of Standardized Semantic Interoperability

This visual example of standardized semantic interoperability shows a provider requesting 'I'd like to order a glucose in the blood lab test'; this is entered into the primary EMR using the code 123ABC, which is then translated to the lab provider's online system as 15074-8, which is their code for a blood glucose test.

Why not just store “glucose lab test?” There are several reasons, but to just highlight a few:

- Descriptions can change. If there is a general label change to improve the readability or even to correct a spelling error, every single chart would have to be updated to reflect the revised label.
- Some systems support multiple languages. If that value is in one language it makes it very difficult to create meaningful data for users of another language. By using a coded value with an associated language-specific description, you can allow the user to select their preferred language beyond English.
- Words can be a confusing way to record data. Words are not always a clear way to communicate with precision and accuracy. We make every effort to say what we mean, but there is always a chance that the person reading the communication will not fully understand the author’s intended meaning. The term “glucose lab test” might be misinterpreted as a specific form of lab even if that was not what the author intended.

With medicine, accuracy is critical. When we record or communicate data it is important that the meaning be conveyed with fidelity or there may be significant risk to the patient. If, for example, a patient is administered the wrong medication due to a miscommunication, there could be a serious adverse reaction. To ensure there is a commonly understood meaning for a piece of information, it is often expressed in a “coded” form like we mentioned above in the glucose lab example. By agreeing on a standard set of codes before data are recorded or communicated, we decrease the likelihood of inferring an unexpected meaning.

There are a large variety of “coding systems” (also known as vocabularies) – methods of expressing complex pre-defined meanings and relationships in portable combinations of letters and numbers. Given the rich nature of medicine and need to be both accurate and precise, many are specific to a particular discipline like pathology, pharmacology, medication, laboratory-related data, or a host of other areas.

In the United States, the federal government has chosen to focus on a few key coding systems for the purposes of data portability. The United States Core Data for Interoperability (USCDI)[35] specifies particular systems by topical area and purpose.

Exhibit 55 Coding Systems by Topic Area

Topic | Coding System
Allergies and Intolerances | Substances: SNOMED CT; Medication Class: SNOMED CT; Medications: RxNorm
Conditions | Encounter Diagnosis: ICD-10-CM, SNOMED CT; Problems: SNOMED CT
Immunizations | CVX, NDC
Medications | RxNorm
Laboratory Tests and Results | LOINC
Vital Signs | LOINC, UCUM
Procedures | HCPCS, CPT, SNOMED CT, CDT, ICD-10-PCS
Smoking Status | SNOMED CT
Race and Ethnicity | CDC-REC
Birth Sex | HL7

In addition to the ability to unambiguously express data, there are some other benefits of using coded data. Each of the individual coding systems we have listed above was purpose-developed to portray “right-sized” information specific to their respective area of focus. Some are incredibly rich and define far more than the human-readable term including additional attributes and references to other concepts.

You might think that systems would directly store some of these facts in one of the standardized code systems we mentioned, but that is extremely rare. Instead, most store information using their own private internal identifiers which map to equivalent values one or more code systems. There are some valid reasons this is done, but extended discussion of them is outside of the scope of this document. Instead, we are going to focus on the implications for cross-systems interoperability.

The reader will note we use the word “equivalent” when discussing mappings. That is intentional. Mappings are not always guaranteed to be “precise” direct identifiers for a specific coded term. Any mapping requires significant investment and expertise and is not something that should be done without exercising great care. Each effort requires subject matter expertise in topics like pathology, pharmacology, and laboratory science as well as deep expertise in the respective code system. The key take-away is that it takes expertise in both of those areas. There are nuances in how specific code systems model data that have serious ramifications in code selection.

The single greatest value of using common vocabularies is they increase the opportunity to exchange data on an organization, city, state, or even national level. This creates important potential applications for research, population health, and quality measurement. We can now see beyond one patient at one facility and start looking at entire populations of patients. We can glean insights across staggering volumes of data to help drive improvements in care that can benefit millions of patients. None of that would be practical without semantic interoperability.

### Syntactic Interoperability

We have discussed how to capture the semantics of a concept, but we have yet to touch on how they might be assembled in a structured way so they can be communicated with meaning. This is known as syntax.

We are not going to go into detail as it exceeds the scope of this handbook, but we do want to touch on a few ideas. Possibly the easiest way to describe syntax is through a grammar in language. Effective communication requires a concept of nouns, verbs, adjectives, etc. as well as a set of rules on how those items can be combined to form a message (a sentence) to convey meaning.

Syntax often appears in two forms:

- Structure of the message contents: The message. There is usually a defined agreement on the “body” of a particular communication.
- Protocols for operations: The agreement on the required and optional series of actions that can be taken on the message during communication. A common example would be when placing an order, the sender will initiate the order and the receiver will acknowledge that the order was received correctly.

A concrete non-medical example is email. An email has a structure – a “to,” a “from,” a “subject,” and a message body. The actions like sending, receiving, and deleting are the operations you can take on an email. The reason emails work so ubiquitously is because there are standards on both the structure and the actions. Without those syntactical agreements you could not effectively send or receive messages – no system would know how to send, receive, or display the message contents. To oversimplify, healthcare systems work like very complex email systems; sending and receiving messages related to admissions, orders, results, and the other rich aspects of care.

It is common to find that specific areas of clinical focus will have their own defined standards for storing and transmitting data. Once you have common syntactical structures (and semantics), you can define methods of communication that specify the types of operations that can be initiated and how they can be used.

The dominant standards body that drives most syntactic healthcare interoperability is Health Level 7 (HL7). You often hear “HL7” expressed in a clinical setting. What might be a bit confusing is that “HL7” is not only the standards organization, but also one of their primary medical record standards, “HL7v2.”[105] One of the reasons the HL7 standards are so prevalent is that they define most core types of messages and actions you might need for normal hospital operations. It covers everything from “basic” patient administration like admission, discharge, and transfer, order management (for everything you could imagine), communication of observations, management of patient demographics, and a host of other activities and data. When you look at a more complex environment like an academic medical center it is extremely common to have individual systems for specialized functions. Interface and messaging standards like HL7 allow for “best of breed” applications to be installed into an overall ecosystem that makes up the medical enterprise.

This approach – leveraging syntactic interoperability standards to allow applications to be broken into components – also allows for federation of functionality beyond the immediate EHR. If you think more broadly and consider the local practice’s medical record system as one component in a state or federal network, you can envision how these interface standards might be used to support patient registries for state-wide immunizations. Each provider might now be able to submit or retrieve records of immunizations to ensure a patient’s list of administered vaccines is up to date. Another common scenario is syndromic surveillance, where organizations are asked to submit arrival diagnosis from the emergency department to monitor outbreaks of diseases.

The evolution of syntactic interoperability is helping drive the interconnected medical system forward. If you have a watch or phone that records data which can now be integrated into your provider’s chart – that is only possible due to standards.

### Policy Interoperability

We described policy interoperability as governance of the allowable use and methods of interacting with the systems and data. To have meaning (semantic) and structural (syntactic) interoperability defines what we could do, not what we are allowed or required to do. Policy defines how and when data may be used as well as the manner and method in which they may be interacted.

One of the most important and widely known interoperability policies within the United States is the “Health Insurance Portability and Accountability Act of 1996” (HIPAA).[106] We typically know HIPAA as having a privacy rule (see Section 2), but it and its subsequent “Administrative Simplification Standard” also contained several other critical provisions:

- Syntactic standards for transactions including eligibility, enrollment, claims, and payment.[107]
- Semantic standards for data including ICD-10, HCPCS, CPT, CDT, and NDC.
- Rules for managing the privacy and security of patient data.[108] This includes definitions of PHI as well as specification of organizations and relationships which could safely exchange PHI in order to provide care.
- Use of Employment Identification Numbers (EIN) in electronic transactions.
- Standardization on use of the National Provider Identifier (NPI) for provider identification.
- Pre-emption of any state laws which do not meet the minimum requirements as defined in the rule. States may offer additional controls and protections in addition to the federal requirements but may not relax any requirements.

This was pivotal legislation as it provided a framework for clinicians and payers (with CMS being a primary one) to interact with each other in a safe, managed form that also mandated minimal standards to help ensure data were able to be communicated more easily without distortion. It also pre-emptively contained major potential problems with unmanaged sharing of patient data sharing that was sure to become an issue with the advent of computer networks.

Several future iterations of legislation followed HIPAA and its additions, encouraging the use of standards for safe management and transmission of patient data:

- Meaningful Use: Part of the American Recovery and Reinvestment Act of 2009, it introduced the concept of a “Certified EHR Technology,” which set criteria expected for all participating medical record systems. This included both semantic and syntactic standards for transitions of care, syndromic surveillance, reportable labs, immunization registries, and several other areas where data are commonly exchanged. It also set new uniform requirements for securing and managing patient data. Critically, it also introduced new standards for eCQMs.
- Trusted Exchange Framework and Common Agreement (TEFCA)[109]: An extremely ambitious policy, TEFCA defines how Qualified Health Information Networks are allowed to function and interact in order to provide much-desired functions like health information networks, registries, or research networks.
- 21st Century Cures Act (Cures Act)[110]: Continuing the march forward from Meaningful Use and leveraging TEFCA, this set of policies promotes greater patient access to data, specifies additional requirements on standard coding systems for semantic interoperability, and introduces new syntactic interoperability requirements focused on emerging standards like Health Level 7 Fast Healthcare Interoperability Resources (HL7 FHIR (https://www.healthit.gov/topic/standards-technology/standards/fhir-fact-sheets)).[111]
- Information Blocking Rule[112]: Part of 21^st^ Century Cures, this item specifically targets tools and vendors that proactively block access and exchange by restricting access to features and functions which facilitate data exchange or implement technologies which make it difficult or more expensive to access data within a system. This is a landmark action by the federal government.

These standards have only relatively recently been mandated by The Office of the National Coordinator for Health Information Technology (ONC) and The Centers for Medicare and Medicaid Services (CMS). To improve the healthcare patients currently receive as well as accelerate growth and development of healthcare services in the United States, the government has set baseline minimum requirements for use of coding system and data exchange standards by vendors and healthcare providers.

## Interoperability Standards

We have previously touched on the idea of standards which help drive interoperability between systems.

Electronic CQMs came to prominence with the advent of The ONC’s Certified EHR requirements. They ultimately included three primary requirements for data capture and reporting [113]:

- Patient data must use the mandated vocabulary standards. Patient data must be able to be expressed using vocabulary standards like SNOMED CT, ICD, RxNorm, LOINC, and others.
- Measure results must be correct. Given a set of sample patients, computed results must match the expected results as defined by the testing tool.
- Systems must use the mandated file formats. Systems must be able to emit patient data and results in the required interoperable standard formats.

What this means to us is that we should be able to take source data from any (certified) medical records system, reliably produce the correct results, and then emit those results in standard formats that can be accepted by downstream applications. In doing so, the expectation is that we should be able to:

- Leverage interoperable data from one or multiple medical record systems with little or no subjective interpretation
- Reliably compute the results of a measure
- Share the results for ingestion into downstream systems like the clinician’s view of the patient, population reporting tools, or even the Quality Payment Program site.

Exhibit 56 Measure Components

This simple graphic shows the measure components for electronic CQMs: Information Model, Logic, Codes / Value Sets

To achieve these goals, eCQMs are broken into a few components which neatly align with existing abstraction methods.

Information Model: The set of basic definitions of concepts that are used in the measure logic. Things like “encounter,” “medication,” “procedure,” or even “time” must have guidance on their meaning, attributes, and use.

Logic: The questions and assertions that compose how the data are to be evaluated. We will not explore this in detail. It is simply important to recognize it as a distinct component.

Codes / Value Sets: For a given component like an “observation vital sign,” the list of allowable vocabulary terms which define it. For example, a heart rate might be defined as LOINC code 8867-4.

The intent is to provide a set of standards that clinicians and developers can rely on as being common, reusable, and reproducible. Revisiting the example from above, we have broken out to more discretely express the way an abstractor is interpreting it, but in a way that starts to align with an electronically computable measure.

## Information Models

Using components of an information model, we can better understand the logic that underpins quality measures. As we look at the question of “did the patient receive medication day of or day after admission?” we touch on several data elements:

- The patient: Everything that makes up the demographics of the specific patient, including their name, their date of birth and age, administrative sex, related medical record identifiers, etc.
- Encounter(s): The purpose/nature of the visit, the related start/end times, the care team, physical location(s), directly related diagnoses, etc.
- Medication(s): (In this case medication administration information) Identifiers that express the specific medication, the start and stop date and time of the administration, the dose, route, and frequency details, as well as potentially the reason for giving (or not giving) the medication.
- Time: Given we are relating the encounter to the medication expressed by “day of or day after,” a shared definition of what “day” means (going back to the prior discussion, is that a 24-hour period or a census day?)

For the purposes of avoiding confusion, each of those elements have structural definitions that include attributes of each concept as well as indicate whether a given attribute is mandatory or can contain multiple entries. That sounds abstract, so let us look at a medication (administration).

A medication administration is a record of a specific medication being given to (or not being given to) a patient. That means we need to, at least minimally, know who is receiving the medication and which medication is being given. We might also include specifics on the dosage, frequency, and route. We would also like to know when the administration occurred. In certain cases, it is also helpful to know why the administration occurred or why it was not given (often referred to as the “negation rationale”).

Exhibit 57 Medication Administration Graphic

This graphic of medication administration shows the components as Patient; Code(s); Timing (Start date/time, Stop date/time); Details (Dosage, Frequency, Route); Reason (For administration, for not administering).

All of these attributes help make up the “type” of thing that a medication administration represents. The list of types is our first step toward defining an information model. The information model describes the types that it includes and how those types can be related. There may be different kinds or classes of types, some which are used within other types. The intention is to define a set of structural definitions and relationships that allow you to compose medical data such that it can be expressed in a known, predictable model.

Having that conformity is a central part of the goal. The intention is to introduce consistency and reusability to reduce the need to constantly transform between systems. That is the benefit of a standard.

In the context of CQMs and clinical decision support, there are two primary information model standards you will encounter.

- Quality Data Model: Originally created by the National Quality Forum, [114] the Quality Data Model (QDM) has historically been the primary information model used for CMS eCQMs since approximately 2010.
- FHIR: HL7 FHIR contains a series of types and classes which are used to compose “resources” – definitions of the elements like patient, encounter, medication, etc. Within FHIR, there is a set of additional modifications specifically to support quality measurement. These additional items and rules (known as profiles) are known as “QI Core.”[115]

QDM is the information model currently in use for CMS quality reporting, but the future is FHIR. They are similar, but where QDM is targeted to particularly quality reporting, FHIR is meant for portrayal of comprehensive portray of EHR data and allows for the purpose-driven extension where required to support both new concepts as well as policy-driven constraints.

### Coded Data

When we define a quality measure such as “did the patient receive a specific medication on the day of or day after hospital admission?” we have a list of the patient’s medications we wish to compare with a pre-defined list of “allowed” medications per the measure definition. We need to know if the patient was administered a particular medication (potentially in a specific form and dose, administered through a particular route). That means we need to have a common definition.

A given measure will contain a list of finite medications, encounter types, etc. which are appropriate for evaluation. In the case of medications, we have standardized vocabularies like RxNorm and NDC. They allow us to portray the specific medications in a codified form, so we avoid subjective interpretation of text data. This is similar to previous abstracted versions in that there is a set of “allowed” medications, but in this case, they are fixed and mandate use of the standard. If a patient’s data do not contain the precise medication in the specified terminology, then the rule will not consider those data.

Given an example of “did the patient receive appropriate venous thromboembolism (VTE) prophylaxis medication?” there would be provided sets of codes (known as a value set [116]) which define that list of medications. Take, for example, the Joint Commission’s “Low Dose Unfractionated Heparin for VTE Prophylaxis” value set.[117] It contains a series of medications (only a subset depicted below), which are expressed using a terminology (in this case RxNorm) and codes. [117]

Exhibit 58 Subset of the Joint Commission’s “Low Dose Unfractionated Heparin for VTE Prophylaxis” Value Set

Medication | Code System | Code
heparin sodium, porcine 1000 UNT/ML Injectable Solution | RXNORM | 1361226
5 ML heparin sodium, porcine 2000 UNT/ML Injection | RXNORM | 1361568
heparin sodium, porcine 20000 UNT/ML Injectable Solution | RXNORM | 1361574

This set of values is exclusively what is used by the measure logic during calculation. That is important to recognize for a few reasons:

- Value sets represent the single, authoritative list of allowed codes for a given portion of measure logic. The value sets do not simply portray “categorized” labels or classes of information. An eCQM needs a prescriptive definition of the precise medication list. This also means all organizations and medical record systems implement identical evaluation based on a single central list verses a variable mechanism that relies on the relative knowledge of the person doing the evaluation. No variation of the individual codes within a value set are allowed or encouraged for the purposes of uniform measurement. In fact, some widely used value sets are copyrighted, require licenses for use, and have stringent restrictions on modification. [118] Value sets are maintained and accessible from the NLM Value Set Authority Center (VSAC) repository (https://vsac.nlm.nih.gov/).
- Value sets are versioned and updated with the measure. A value set is rarely “static.” The expectation is that it is clinically relevant. As care protocols, medications, procedures, and even vocabulary coding evolve, a value is updated to reflect those improvements. Value sets are most often versioned annually with updates to the related measure. In the above example, should a medication be taken off the market, it will be removed from the value set. Likewise, should a new medication be introduced and deemed appropriate by the measure steward, it will be added. The easiest example of this is the list of annual allowed influenza medications. Each year these are versioned as the CDC choose the appropriate target formulation. The value sets are updated to contain the new formulations and remove the older ones.
- Mostly critically, the data in the patient record are expected to be coded in the vocabularies used in the value sets. As we mentioned above, a value set is not simply a suggested list of general categories of medications, encounter types, procedures, etc. It represents a finite, fixed list in one or more coded vocabularies. That means that the target patient data being evaluated must also be accessible in the coded vocabularies used in that value set. Even if the data is visible in the chart through a note or some other screen, if it is not accessible in the required coding standard, it will be ignored.

That last point is a critical departure from abstracted quality measurement and bears repeating – the data being evaluated in the patient record must be accessible in the required vocabulary coding standard or it will not be considered in the measure. This is the single largest challenge most organizations face when transitioning to eCQMs and where a large portion of effort and expertise are invested. The patient record may be data rich, but information poor. Items recorded in text notes, flow sheets, or other areas of the chart may not be coded in a way that allows them to be exposed in the vocabularies that a measure’s value sets use.

This is why policies are such an important part of the interoperability mission. Given the variety of coding systems that exist, it would be difficult to have measures all use a random series of choices for representation of key portions of the patient chart. Guiding the determination of which vocabularies are appropriate for a given value set are policies that mandate the use of USCDI [35], which we mentioned in the Interoperability section. USCDI helps to align, or “harmonize” the choice of vocabulary coding standards across measures and related value sets for a given class of data like an encounter, medication, allergy, etc. Policy standards help to ensure semantic compatibility across measures.

### Successful Projects Start with Data Evaluation

Simply having an EHR, even with coded data, will not ensure that the data elements captured are in the vocabularies required by the measure standards. Previously, we mentioned the idea of code mapping where we potentially have a system-specific value for something like a medication ID or even a vital sign. When engaging in an initiative where you intend to use national standards for data exchange or measurement, anticipate that the effort should start with several initial “data assessment” tasks:

- Are the data in the EHR captured in discrete coded forms? If the medical record system or care teams make liberal use of text strings or text notes, then it will be more difficult and time-consuming to extract coded forms required for electronic exchange or measurement. To do so will certainly require extensive technology investment and may, in some cases, violate requirements for regulatory reporting.
- Are the coded forms directly accessible in the preferred national vocabulary standards? If there are discrete coded elements captured through medication systems, flow sheets, or other aspects of required data, they need to be accessible in the required vocabulary standards as defined by either policy or the measure (which are, hopefully, “harmonized”). Each individual data point must be able to be expressed (either directly or indirectly) through vocabulary standards like ICD-10, SNOMED CT, LOINC, RxNorm, etc. as required.
- Over which time periods are various code systems accessible? In some cases, as vocabulary standards are introduced to organizations and EHRs, they will be available for more recent data, but possibly not historical data. This is a common situation to encounter. If you are doing longer term longitudinal reporting, be sure to evaluate how far back in time any coded data exist.

When engaging on an electronic measurement effort it is helpful to first evaluate which measures you intend on calculating, gathering information on each major domain of information (labs, medications, patient demographics, etc.) are involved, and then performing an assessment on the availability and quality of any required data elements. By performing an assessment on data quality in advance, you can help ensure proper project planning and set expectations on what is possible early on. If there are gaps in mapping and coding, those should be identified at the initiation of an effort so you can engage the required subject matter expert.