# VI LIST OF RESEARCH ACTIVE IN 2018

Research with an asterisk indicates that the work was newly awarded in 2018.

AHRQ Health Services Research Demonstration and Dissemination Grants (R18)
Principal Investigator | Organization | Project Title | Short Description | Technology
Epstein, Jeff N. | Cincinnati Children’s Hospital Medical Center | Improving ADHD Behavioral Care Quality in Community-Based Pediatric Settings (https://healthit.ahrq.gov/ahrq-funded-projects/improving-adhd-behavioral-care-quality-community-based-pediatric-settings) | This project will enhance an existing Web-based portal, myADHDportal.com, to integrate behavioral tools alongside existing medication management tools for attention deficit hyperactivity disorder (ADHD). | Patient Portal, Internet
Jack, Brian | Boston Medical Center | Implementation and Dissemination of ‘Gabby,’ a Health Information Technology System for Young Women, into Community-Based Clinical Sites (https://healthit.ahrq.gov/ahrq-funded-projects/implementation-and-dissemination-gabby-health-information-technology-system) | This project will develop and disseminate an innovative communication system to identify and mitigate health risks for young African American women before pregnancy as a means of reducing health disparities in birth outcomes. | Artificial Intelligence, Virtual Reality
Kroth, Philip | University of New Mexico | Minimizing Stress, Maximizing Success of Physician’s Use of Health Information (https://healthit.ahrq.gov/ahrq-funded-projects/minimizing-stress-maximizing-success-physicians-use-health-information) | This project identified strategies that mitigate the stress associated with provider use of health information and communications technologies. | Electronic Health Record/Electronic Medical Record
McTigue, Kathleen M. | University of Pittsburgh at Pittsburgh | Maintaining Activity and Nutrition through Technology-Assisted Innovation in Primary Care (https://healthit.ahrq.gov/ahrq-funded-projects/maintaining-activity-and-nutrition-through-technology-assisted-innovation) | This project implemented an electronic health record-based weight loss maintenance intervention and found medium-term success for patients assigned to the intervention. | Electronic Health Record/Electronic Medical Record, Patient Portal
Solberg, Leif | HealthPartners Institute | Optimizing the Value of Patient-Reported Outcome Measures in Improving Care Delivery through Health Information Technology (https://healthit.ahrq.gov/ahrq-funded-projects/optimizing-value-patient-reported-outcome-measures-improving-care-delivery) | This project will identify orthopedic clinical outcome measures that are most important to patients, and study the impact on satisfaction and outcomes when this information is provided to patients and their doctors. | Electronic Health Record/Electronic Medical Record, Patient-Generated Health Data
AHRQ Patient Centered Outcomes Research (PCOR) Mentored Clinical Investigator Award (K08)
Principal Investigator | Organization | Project Title | Short Description | Technology
Sharifi, Mahnoos H. | Yale University | Using Electronic Health Records to Support Decision-Making in Pediatric Obesity Care (https://healthit.ahrq.gov/ahrq-funded-projects/using-electronic-health-records-support-decision-making-pediatric-obesity-care) | This project will evaluate and compare different tools within electronic health records to assist pediatric primary care clinicians with providing higher quality childhood obesity care to help slow weight gain in children with obesity. | Clinical Decision Support System, Electronic Health Record/Electronic Medical Record
AHRQ Small Research Grant Program (R03)
Principal Investigator | Organization | Project Title | Short Description | Technology
Ellis, Charles | East Carolina University | Speech Telerehabilition After Stroke: Proof-of-Concept and Feasibility (https://healthit.ahrq.gov/ahrq-funded-projects/speech-telerehabilition-after-stroke-proof-concept-and-feasibility) | This project will conduct a proof-of-concept and feasibility study of aphasia telerehabilitation for stroke patients with aphasia residing in rural North Carolina. | Telemedicine System
Mendonca, Eneida | University of Wisconsin - Madison | Virtualized Homes: Tools for Better Discharge Planning (https://healthit.ahrq.gov/ahrq-funded-projects/virtualized-homes-tools-better-discharge-planning) | This research linked a web viewer for 3D models of patient homes to an electronic health record so that the models could be viewable and annotated from within a patient’s record for better discharge planning. | Artificial Intelligence, Electronic Health Record/Electronic Medical Record, Virtual Reality, Remote Patient Monitoring, Public Health Informatics
Saleem, Jason J. | University of Louisville | Ambulatory Clinic Exam Room Design With Respect to Computing Devices to Enhance Patient Centeredness (https://healthit.ahrq.gov/ahrq-funded-projects/ambulatory-clinic-exam-room-design-respect-computing-devices-enhance-patient) | This project studied the impact of changing the computing layout in a clinical exam room and evaluated its impact on workflow and patient centeredness. | Electronic Health Record/Electronic Medical Record, Architecture
Disseminating and Implementing Evidence from Patient Centered Outcomes Research in Clinical Practice Using Mobile Health Technology (R21)
Principal Investigator | Organization | Project Title | Short Description | Technology
Abujarad, Fuad | Yale University | Patient-Centered Virtual Multimedia Interactive Informed Consent (VIC) (https://healthit.ahrq.gov/ahrq-funded-projects/patient-centered-virtual-multimedia-interactive-informed-consent-vic) | This project developed the Patient-Centered Virtual Multimedia Interactive Informed Consent tool and found that patients who used the tool had increased knowledge and higher satisfaction than control patients. | Consumer Health Informatics, Mobile Device
Chrischilles, Elizabeth | University of Iowa | Design and Testing of a Mobile Cardiovascular Risk Service With Patient Partners (https://healthit.ahrq.gov/ahrq-funded-projects/design-and-testing-mobile-cardiovascular-risk-service-patient-partners) | This project developed and tested a mobile health application for a centralized, pharmacist-managed cardiovascular risk service to improve patient engagement in self-management of cardiovascular risk. | Clinical Messaging, Mobile Device, Mobile Phone, Patient-Generated Health Data
Connelly, Mark Andrew | Children’s Mercy Kansas City | Registry-Assisted Dissemination of Mobile Pain Management for Youth With Arthritis (https://healthit.ahrq.gov/ahrq-funded-projects/registry-assisted-dissemination-mobile-pain-management-youth-arthritis) | The researchers developed a mobile health application to distribute evidence-based pain self-management strategies to patients with juvenile idiopathic arthritis. | Data Warehouse, Mobile Device, Registry, Patient-Generated Health Data
Oreskovic, Nicolas M. | Massachusetts General Hospital | An Integrated Closed-Loop Feedback System for Pediatric Cardiometabolic Disease (https://healthit.ahrq.gov/ahrq-funded-projects/integrated-closed-loop-feedback-system-pediatric-cardiometabolic-disease) | The project team will develop a set of mHealth tools capable of collecting health behavior information and evaluate whether providing clinical feedback on these behaviors reduces obesity and improves health behaviors among at-risk families. | Mobile Phone, Text Messaging, Patient-Generated Health Data, Mobile Device
Rudin, Robert Samuel | RAND Corporation | Using mHealth and Patient-Reported Outcomes to Deliver Evidence-Based Asthma Care (https://healthit.ahrq.gov/ahrq-funded-projects/using-mhealth-and-patient-reported-outcomes-deliver-evidence-based-asthma-care) | This research developed and evaluated a mobile health application for patients with asthma. | Mobile Device, Mobile Phone, Patient-Centered Health Data, Electronic Health Record/Electronic Medical Record
Schnall, Rebecca | Columbia University | Use of mHealth Technology for Supporting Symptom Management in Underserved Persons Living with HIV (https://healthit.ahrq.gov/ahrq-funded-projects/use-mhealth-technology-supporting-symptom-management-underserved-persons-living) | This project tested a mobile health application for HIV symptom management for people living with HIV and found an improvement in symptoms. | Mobile Device, Mobile Phone, Consumer Health Informatics
Shah, Nirmish R. | Duke University | Use of Mobile Technology To Improve Acute Care Utilization in Sickle Cell Disease (https://healthit.ahrq.gov/ahrq-funded-projects/use-mobile-technology-improve-acute-care-utilization-sickle-cell-disease) | This project will evaluate the impact of a sickle cell disease mobile application on reducing acute care visits by patients with the condition. | Mobile Device, Personal Health Record, Mobile Phone, Consumer Health Informatics, Patient-Generated Health Data
Tulu, Bengisu | Worcester Polytechnic Institute | TJR Guru--a Mobile App for Shared Informed Decisionmaking in Total Joint Replacement Surgery (https://healthit.ahrq.gov/ahrq-funded-projects/tjr-guru-mobile-app-shared-informed-decisionmaking-total-joint-replacement) | This project developed and pilot-tested TJR App, a mobile application designed to help patients with osteoarthritis track their pain and activity, and found that app users were more likely to track symptoms consistently, when compared to non-users. | Mobile Device, Consumer Health Informatics, Patient-Generated Health Data
AHRQ Health Services Research Projects (R01)
Principal Investigator | Organization | Project Title | Short Description | Technology
Adelman, Jason Stuart | Columbia University Health Sciences | Develop and Validate Health IT Safety Measures To Capture Violations of the Five Rights of Medication Safety (https://healthit.ahrq.gov/ahrq-funded-projects/develop-and-validate-health-it-safety-measures-capture-violations-five-rights) | This project will develop and validate new measures needed for automatically identifying violations of the “Five Rights of Medication Safety”: right patient, right dose, right medication, right route, and right frequency. | Computerized Provider Order Entry System, Electronic Health Record/Electronic Medical Record
Adelman, Jason Stuart | Columbia University Health Sciences | Providing Evidence and Developing a Toolkit to Accelerate the Adoption of Patient Photographs in Electronic Health Records (https://healthit.ahrq.gov/ahrq-funded-projects/providing-evidence-and-developing-toolkit-accelerate-adoption-patient) | This study will evaluate the effectiveness of patient photographs displayed in electronic health record systems for preventing wrong-patient errors. | Computerized Provider Order Entry System, Electronic Health Record/Electronic Medical Record
Aguilera, Adrian | University of California, Berkeley | Improving Diabetes and Depression Self-management Via Adaptive Mobile Messaging (https://healthit.ahrq.gov/ahrq-funded-projects/improving-diabetes-and-depression-self-management-adaptive-mobile-messaging) | This project will develop and test a personalized motivational text messaging intervention to improve management of diabetes and depression in low-income populations. | Artificial Intelligence, Machine Learning, Mobile Phone, Text Messaging, Patient Generated Health Data
Alcantara, Carmela* | Columbia University | Using eHealth to Expand Access to Cognitive Behavioral Therapy for Insomnia in Hispanic Primary Care Patients (https://healthit.ahrq.gov/ahrq-funded-projects/using-ehealth-expand-access-cognitive-behavioral-therapy-insomnia-hispanic) | This project evaluates the effectiveness, barriers, and cost of a Spanish-language electronic health intervention to treat chronic insomnia in Hispanic patients. | Internet, Mobile Device, Patient Generated Health Data
Bajaj, Jasmohan S.* | Virginia Commonwealth University | Health IT-Generated PROs to Improve Outcomes in Cirrhosis (https://healthit.ahrq.gov/ahrq-funded-projects/health-it-generated-pros-improve-outcomes-cirrhosis) | This project will test the effectiveness of using patient-reported outcomes for cirrhosis collected with Patient Buddy and EncephalApp on hospital readmissions. | Patient-Generated Health Data, Mobile Device, Secure Messaging
Bates, David | Brigham and Women’s Hospital | Ensuring Safe Performance of Electronic Health Records (https://healthit.ahrq.gov/ahrq-funded-projects/ensuring-safe-performance-electronic-health-records) | This project will refine the Leapfrog Computerized Provider Order Entry (CPOE)/Electronic Health Record (EHR) test – a “flight simulator” for EHRs with CPOE which evaluates the safety performance of EHRs after deployment, with a particular focus on high impact patient safety and medication safety problems. | Computerized Provider Order Entry System, Electronic Health Record/Electronic Medical Record
Cummins, Mollie Rebecca | University of Utah | Electronic Exchange of Poisoning Information (https://healthit.ahrq.gov/ahrq-funded-projects/electronic-exchange-poisoning-information) | The objective of this study is to develop, implement, and evaluate a replicable, scalable infrastructure for health information exchange supported emergency department and poison control centers collaboration. | Health Information Exchange
Grannis, Shaun | Indiana University-Purdue University at Indianapolis | Enhancing Patient Matching in Support of Operational Health Information Exchange (https://healthit.ahrq.gov/ahrq-funded-projects/enhancing-patient-matching-support-operational-health-information-exchange) | This project will enhance novel algorithms for matching patient health information across data sources, implement them, and evaluate their accuracy. | Health Information Exchange
Lambert, Bruce | Northwestern University | Preventing Wrong-Drug and Wrong-Patient Errors With Indication Alerts in CPOE Systems (https://healthit.ahrq.gov/ahrq-funded-projects/preventing-wrong-drug-and-wrong-patient-errors-indication-alerts-cpoe-systems) | The project will develop and test a large set of alerts at two large health systems to demonstrate that alerts can help prevent wrong-drug and wrong-patient errors and improve the completeness of the problem list. | Clinical Decision Support System, Computerized Provider Order Entry System, Electronic Health Record/Electronic Medical Record
Malone, Daniel C.* | University of Arizona | Meaningful Drug Interaction Alerts (https://healthit.ahrq.gov/ahrq-funded-projects/meaningful-drug-interaction-alerts) | This project proposes a novel proactive system to reduce alert burden and thereby increase attention to situations in which patient safety is at risk. | Clinical Decision Support System, Computerized Provider Order Entry System, Medication Management System
Marcin, James | University of California, Davis | School-Based Tele-Physiatry Assistance for Rehabilitative and Therapeutic Services for Children with Special Health Care Needs Living in Rural and Underserved Communities (https://healthit.ahrq.gov/ahrq-funded-projects/school-based-tele-physiatry-assistance-rehabilitative-and-therapeutic-services) | This project will determine the impact of using telemedicine to serve children with special healthcare needs living in rural and underserved communities. | Telemedicine System
McCarty, Carolyn A. | Seattle Children’s Hospital | Improving Teen Care With Health (https://healthit.ahrq.gov/ahrq-funded-projects/improving-teen-care-health-it) IT | This project will develop and test a Web-based Health Assessment (iHA) for adolescents to screen for health risk behaviors, with an aim towards providing prevention and risk reduction counseling. | Clinical Decision Support System, Consumer Health Informatics, Patient-Generated Health Data, Internet
Patel, Vimla L. | New York Academy of Medicine | Impact of Meaningful Use on Clinical Workflow in Emergency Departments (https://healthit.ahrq.gov/ahrq-funded-projects/impact-meaningful-use-clinical-workflow-emergency-departments) | This project investigates how the Meaningful Use criteria affects the information seeking, team-interaction, and decisionmaking activities of emergency department clinicians at two urban hospitals. | Electronic Health Record/Electronic Medical Record, Radio Frequency Identification Device, Standards and Classification, Clinical Documentation, Clinical Messaging, Geographic Information System
Ratwani, Raj M. | MedStar Health Research Institute | Developing Evidence-Based, User-Centered Design and Implementation Guidelines to Improve Health Information Technology Usability (https://healthit.ahrq.gov/ahrq-funded-projects/developing-evidence-based-user-centered-design-and-implementation-guidelines) | This project will provide an evidence base to better inform user-centered design and implementation processes to improve health information technology, usability, and safety. | Artificial Intelligence, Machine Learning, Natural Language Processing System, Standards and Classification, Clinical Informatics, Clinical Information System
Ratwani, Raj M.* | MedStar Health Research Institute | Improving Patient Safety and Clinician Cognitive Support Through eMAR Redesign (https://healthit.ahrq.gov/ahrq-funded-projects/improving-patient-safety-and-clinician-cognitive-support-through-emar-redesign) | This study will examine usability and safety hazards of electronic medication administration records, with a focus on communication and information flow between health information technology applications. | Bar Coding, Medication Management System, Natural Language Processing System, Electronic Prescribing, Computerized Provider Order Entry System, Administrative System, Pharmacy information System
Reed, Mary* | Kaiser Foundation Research Institute | Patient Choice of Telemedicine Encounters (https://healthit.ahrq.gov/ahrq-funded-projects/patient-choice-telemedicine-encounters) | This project will examine the quality and safety impact of patient-initiated telemedicine visits with primary care providers. | Telemedicine System
Schiff, Gordon David | Brigham and Women’s Hospital | Enhancing Medication CPOE Safety and Quality by Indications-Based Prescribing (https://healthit.ahrq.gov/ahrq-funded-projects/enhancing-medication-cpoe-safety-and-quality-indications-based-prescribing) | This project convened stakeholder panels to inform the development of an indications-enabled computerized prescriber order entry system. | Computerized Provider Order Entry System, Electronic Prescribing, Medication Management System
Schmajuk, Gabriela* | University of California, San Francisco | Incorporating PRO Data Into RA Clinical Encounters Using Health-IT (PACT) (https://healthit.ahrq.gov/ahrq-funded-projects/incorporating-pro-data-ra-clinical-encounters-using-health-it-pact) | This project will develop and evaluate an electronic dashboard to display patient reported outcomes for patients with rheumatoid arthritis that will facilitate clinician and patient conversations about their care. | Dashboard, Electronic Health Record/Electronic Medical Record, Patient-Generated Health Data
Schnall, Rebecca | Columbia University Health Sciences | The Wise App Trial for Improving Health Outcomes in PLWH (https://healthit.ahrq.gov/ahrq-funded-projects/wise-app-trial-improving-health-outcomes-plwh) | This study will design a user-centered smartphone application linked to a smart pill box with the goal of improving medication adherence for people living with HIV. | Mobile Phone
Schoenthaler, Antoinette* | New York University School of Medicine | i-Matter: Investigating an mHealth Texting Tool for Embedding Patient-Reported Data into Diabetes Management (https://healthit.ahrq.gov/ahrq-funded-projects/i-matter-investigating-mhealth-texting-tool-embedding-patient-reported-data) | This project will evaluate the effects of a technology-based patient-reported outcomes system on patient management of type 2 diabetes in primary care practices. | Electronic Health Record/Electronic Medical Record, Mobile Phone, Text Messaging
Senathirajah, Yalini | SUNY Downstate Medical Center | Finding the Safer Way: Novel Interaction Design Approaches to Health IT Safety (https://healthit.ahrq.gov/ahrq-funded-projects/finding-safer-way-novel-interaction-design-approaches-health-it-safety) | This project will study the impact of design on providers’ interactions with the electronic health record and identify strategies to enhance design to improve patient safety. | Electronic Health Record/Electronic Medical Record, Standards and Classification, Architecture
Shapiro, Jason S. | Mount Sinai School of Medicine | Advancing Quality Measurement and Care Improvement with Health Information Exchange (https://healthit.ahrq.gov/ahrq-funded-projects/advancing-quality-measurement-and-care-improvement-health-information-exchange) | The purpose of this project was to leverage existing health information exchange data to improve quality measurement of two measures for potentially preventable emergency department visits. | Health Information Exchange
Siegel, Corey | Dartmouth College | Evaluating a Prediction Tool and Decision Aid for Patients with Crohn’s Disease (https://healthit.ahrq.gov/ahrq-funded-projects/evaluating-prediction-tool-and-decision-aid-patients-crohns-disease) | To address challenges with treating Crohn’s disease, the project will develop a statistical model that predicts Crohn’s disease severity and a Web-based decision tool to help patients understand their treatment options. | Consumer Health Informatics
Sockolow, Paulina | Drexel University | Information Needs of Homecare Nurses During Admission and Care Planning (https://healthit.ahrq.gov/ahrq-funded-projects/information-needs-homecare-nurses-during-admission-and-care-planning) | This project will analyze and model the information requirements, decisionmaking, and workflow of homecare nurses admitting patients and characterize if and how health information technology systems support their needs. | Electronic Health Record/Electronic Medical Record
Stockwell, Melissa S. | Columbia University | PRISM: Personalized Reminders for Immunizations using Short Messaging Systems (https://healthit.ahrq.gov/ahrq-funded-projects/prism-personalized-reminders-immunizations-using-short-messaging-systems) | This study will compare the use of personalized HPV vaccine text message reminders to conventional text message reminders among minority adolescents in a randomized trial. | Mobile Phone, Text Messaging
Stockwell, Melissa S. | Columbia University Health Sciences | SINC: Synchronized Immunization Notifications (https://healthit.ahrq.gov/ahrq-funded-projects/sinc-synchronized-immunization-notifications) | This project will create and evaluate the impact of immunization reminders using information from an electronic health record combined with an immunization information system. | Clinical Decision Support System, Registry
Toh, Darren* | Harvard Pilgrim Health Care, Inc. | Improving Missing Data Analysis in Distributed Research Networks (https://healthit.ahrq.gov/ahrq-funded-projects/improving-missing-data-analysis-distributed-research-networks) | This project aims to refine and develop methods to address missing electronic health record data to improve data quality and research validity. | Database, Electronic Health Record/Electronic Medical Record, Machine Learning, Architecture
Turchin, Alexander | Brigham and Women’s Hospital | Identification of Patients with Low Life Expectancy (https://healthit.ahrq.gov/ahrq-funded-projects/identification-patients-low-life-expectancy) | This project will use natural language processing and dynamic logic to create a high-fidelity model of risk of death to identify patients with low life expectancy. | Artificial Intelligence, Natural Language Processing System
Vest, Joshua Ryan | Indiana University-Purdue University at Indianapolis | Use of Push and Pull Health Information Exchange Technologies by Ambulatory Care Practices and the Impact on Potentially Avoidable Health Care Utilization (https://healthit.ahrq.gov/ahrq-funded-projects/use-push-and-pull-health-information-exchange-technologies-ambulatory-care) | This project will clarify the relationship between “pull” and “push” health information exchange usage in primary care settings, and determine the impact of each approach on potentially avoidable and costly health care utilization. | Health Information Exchange, Architecture
Weiner, Saul | University of Illinois at Chicago | Integrating Contextual Factors into Clinical Decision Support to Reduce Contextual Error and Improve Outcomes in Ambulatory Care (https://healthit.ahrq.gov/ahrq-funded-projects/integrating-contextual-factors-clinical-decision-support-reduce-contextual) | This research will explore whether providing clinicians with contextual information at the point of care through the use of clinical decision s (https://healthit.ahrq.gov/ahrq-funded-projects/integrating-contextual-factors-clinical-decision-support-reduce-contextual)upport can reduce contextual errors, improve patient healthcare outcomes, and reduce misuse and overuse of medical services. | Clinical Decision Support System, Electronic Health Record/Electronic Medical Record
Xiong, Glen | University of California, Davis | Comparison of Asynchronous Telepsychiatry Alongside Synchronous Telepsychiatry in Skilled Nursing Facilities (https://healthit.ahrq.gov/ahrq-funded-projects/comparison-asynchronous-telepsychiatry-alongside-synchronous-telepsychiatry) | This project will evaluate the comparative effectiveness of asynchronous telepsychiatry versus synchronous telepsychiatry in a skilled nursing facility population using a 12-month randomized controlled trial. | Telemedicine System
Yellowlees, Peter M. | University of California, Davis | A Clinical Trial to Validate an Automated Online Language Interpreting Tool With Hispanic Patients Who Have Limited English Proficiency (https://healthit.ahrq.gov/ahrq-funded-projects/clinical-trial-validate-automated-online-language-interpreting-tool-hispanic) | This project aims to improve access to high quality mental health services for diverse populations by implementing asynchronous telepsychiatry consultations combined with automated online interpreting. | Telemedicine System
Zhou, Li | Brigham and Women’s Hospital | Encoding and Processing Patient Allergy Information in EHRs (https://healthit.ahrq.gov/ahrq-funded-projects/encoding-and-processing-patient-allergy-information-ehrs) | The research team developed and evaluated a natural language processing allergy module that was used to study different types of allergies in an electronic health record. | Artificial Intelligence, Natural Language Processing System
Zhou, Li | Brigham and Women’s Hospital | NLP to Improve Accuracy and Quality of Dictated Medical Documents (https://healthit.ahrq.gov/ahrq-funded-projects/nlp-improve-accuracy-and-quality-dictated-medical-documents) | This project will study the impact of errors in medical documents on quality of care and develop innovative natural language processing methods to automatically detect errors so that physicians can correct the documents before finalizing them in the electronic health record. | Artificial Intelligence, Clinical Documentation, Machine Learning, Natural Language Processing System, Voice Recognition
Zhou, Li | Brigham and Women’s Hospital | Improving Allergy Documentation and Clinical Decision Support in the Electronic Health Record (https://healthit.ahrq.gov/ahrq-funded-projects/improving-allergy-documentation-and-clinical-decision-support-electronic-health) | This project will redesign approaches for collecting and using allergy information with the goal of improving healthcare quality and safety, including completeness and accuracy of allergy data. | Artificial Intelligence, Clinical Decision Support System, Electronic Health Record/Electronic Medical Record, Natural Language Processing System, Architecture, Clinical Documentation
Exploratory and Developmental Grant to Improve Health Care Quality through Health Information Technology (IT) (R21)
Principal Investigator | Organization | Project Title | Short Description | Technology
Abraham, Joanna | University of Illinois at Chicago | An Etiology for Medication Ordering Errors in Computerized Provider Order Entry Systems (https://healthit.ahrq.gov/ahrq-funded-projects/etiology-medication-ordering-errors-computerized-provider-order-entry-systems) | This project will evaluate a computerized provider order entry (CPOE)-based function—medication voiding—that can be used to prospectively identify and document medication ordering errors. | Computerized Provider Order Entry System, Electronic Health Record/Electronic Medical Record, Electronic Prescribing
Adelman, Jason Stuart | Columbia University | Assess Risk of Wrong-Patient Errors in an EMR That Allows Multiple Records Open (https://healthit.ahrq.gov/ahrq-funded-projects/assess-risk-wrong-patient-errors-emr-allows-multiple-records-open) | This project compared the risk of orders placed on the wrong electronic patient record when providers were limited to having one patient record open at a time versus up to four and found no difference in errors between the two. | Computerized Provider Order Entry System, Electronic Health Record/Electronic Medical Record
Avidan, Michael | Washington University | Anesthesiology Control Tower: Feedback Alerts to Supplement Treatment (ACTFAST) (https://healthit.ahrq.gov/ahrq-funded-projects/anesthesiology-control-tower-feedback-alerts-supplement-treatment-actfast) | The goal of this project is to develop and evaluate an air traffic control-like command center for operating rooms. | Artificial Intelligence, Clinical Decision Support System, Dashboard, Electronic Health Record/Electronic Medical Record, Machine Learning, Mobile Device, Telemedicine System
Bardach, Naomi S. | University of California, San Francisco | Novel IT To Create Patient-Integrated Quality Improvement (https://healthit.ahrq.gov/ahrq-funded-projects/novel-it-create-patient-integrated-quality-improvement) | This research created, piloted, and evaluated FIQS, the Family Input to Quality and Safety tool, that allows pediatric patients and their caregivers to provide safety reports regarding their inpatient care. | Dashboard, Mobile Device, Patient-Generated Health Data, Patient Portal
Bauer, Nerissa San Luis | Indiana University-Purdue University at Indianapolis | Improving Anxiety Detection in Pediatrics Using Health Information Technology (https://healthit.ahrq.gov/ahrq-funded-projects/improving-anxiety-detection-pediatrics-using-health-information-technology) | This project integrated a validated anxiety-specific screening tool in an existing clinical decision support system and tested it with a randomized feasibility pilot that found the tool did not increase detection of anxiety in pediatric primary care. | Clinical Decision Support System
Cartmell, Kathleen Buford | Medical University of South Carolina | Reducing Hospital Readmission Rates by Implementing an Inpatient Tobacco Cessation Service Driven by Interactive Voice Recognition Technology (https://healthit.ahrq.gov/ahrq-funded-projects/reducing-hospital-readmission-rates-implementing-inpatient-tobacco-cessation) | This study evaluated a smoking cessation program using interactive voice recognition technology and found that the intervention successfully reduced unplanned hospital readmissions and costs. | Voice Recognition, Telemedicine System, Remote Patient Monitoring
Chui, Michelle Anne* | University of Wisconsin - Madison | CancelRx: A Health IT Tool to Decrease Medication Discrepancies in the Outpatient Setting (https://healthit.ahrq.gov/ahrq-funded-projects/cancelrx-health-it-tool-decrease-medication-discrepancies-outpatient-setting) | This project will examine the impact of implementing the e-Prescribing standard CancelRx on outpatient medication discrepancies and on clinic and pharmacy workflows. | Electronic Prescribing, Pharmacy Information System
Cohen, Lindsey | Georgia State University | Relieving Anxiety in Children Undergoing Radiation Therapy Through Virtual Preparation (https://healthit.ahrq.gov/ahrq-funded-projects/relieving-anxiety-children-undergoing-radiation-therapy-though-virtual-preparation) | This research developed an interactive and engaging computer tablet-based, virtual program to prepare children with cancer for radiation therapy. | Consumer Health Informatics, Mobile Phone, Mobile Device, Virtual Reality
Dalal, Anuj K. | Brigham and Women’s Hospital | Interactive Patient-Centered Discharge Toolkit To Promote Self-Management During Transitions (https://healthit.ahrq.gov/ahrq-funded-projects/interactive-patient-centered-discharge-toolkit-promote-self-management-during) | This project will implement and evaluate a previously developed, interactive, patient-centered discharge toolkit to improve the transition of care from the inpatient to outpatient settings. | Mobile Device, Mobile Phone, Patient Portal
Dexheimer, Judith W. | Cincinnati Children’s Hospital Medical Center | Optimal Methods for Notifying Clinicians About Epilepsy Surgery Patients (https://healthit.ahrq.gov/ahrq-funded-projects/optimal-methods-notifying-clinicians-about-epilepsy-surgery-patients) | This project will integrate an existing Natural Language Processing system into neurology clinical practice and develop a decision support mechanism to alert providers about patients with epilepsy who are potential surgical candidates with the goal to shorten the time to surgical evaluation for eligible patients. | Artificial Intelligence, Clinical Decision Support System, Machine Learning, Natural Language Processing System
Dixon, Brian | Indiana University-Purdue University at Indianapolis | Exploring the Utilization of and Outcomes from Health Information Exchange in Emergency Settings (https://healthit.ahrq.gov/ahrq-funded-projects/exploring-utilization-and-outcomes-health-information-exchange-emergency) | This project will examine health information exchange (HIE) usage patterns, the barriers and facilitators of HIE use, and the impact of HIE use by emergency department clinicians. | Data Warehouse, Health Information Exchange
Cartmell, Kathleen Buford | Medical University of South Carolina | A Geofencing-Based Adaptive Messaging System to Support Patient Self-Management of a Low-Sodium Diet in Hypertension (https://healthit.ahrq.gov/ahrq-funded-projects/geofencing-based-adaptive-messaging-system-support-patient-self-management-low) | This study evaluated a smoking cessation program using interactive voice recognition technology and found that the intervention successfully reduced unplanned hospital readmissions and costs. | Voice Recognition
Dorsch, Michael | University of Michigan at Ann Arbor | Evaluation of the Impact of Telemedicine on Management of Rheumatoid Arthritis (https://healthit.ahrq.gov/ahrq-funded-projects/evaluation-impact-telemedicine-management-rheumatoid-arthritis) | This project will develop and test the effectiveness of a mobile application to help patients with hypertension reduce their dietary sodium intake by using mobile notifications at grocery stores and restaurants. | Consumer Health Informatics, Geographic Information System, Mobile Device, Patient Generated Health Data
Ferucci, Elizabeth D. | Alaska Native Tribal Health Consortium | StartSmart(TM): Health Information Technology to Improve Adherence to Prenatal Guidelines (https://healthit.ahrq.gov/ahrq-funded-projects/startsmarttm-health-information-technology-improve-adherence-prenatal) | This project will evaluate the impact of telemedicine rheumatology via video teleconference capability on quality of care outcomes and process measures for rheumatoid arthritis. | Telemedicine System
Gance-Cleveland, Bonnie | University of Colorado, Denver | Exploring the Utilization of and Outcomes from Health Information Exchange in Emergency Settings (https://healthit.ahrq.gov/ahrq-funded-projects/exploring-utilization-and-outcomes-health-information-exchange-emergency) | This project will develop a mobile health application to improve screening, intervention, and referrals in the care of pregnant women. | Mobile Device, Consumer Health Informatics
Goss, Foster R. | University of Colorado, Denver | Natural Language Processing To Identify and Rank Clinically Relevant Information for EHRs in the Emergency Department (https://healthit.ahrq.gov/ahrq-funded-projects/natural-language-processing-identify-and-rank-clinically-relevant-information) | This project developed a natural language processing electronic health record search tool that automatically identifies and ranks relevant clinical information based on a patient’s presenting complaint within the emergency department setting. | Artificial Intelligence, Electronic Health Record/Electronic Medical Record, Machine Learning, Natural Language Processing System
Gray, Stacy W. | Beckman Research Institute - City of Hope | Empowering Cancer Patients Through Innovations in Information Technology-Based Reporting of Precision Medicine (https://healthit.ahrq.gov/ahrq-funded-projects/empowering-cancer-patients-through-innovations-information-technology-based) | This project will provide patients direct access to their cancer genomic sequencing results through a Web-based portal, Helping Oncology Patients Explore-Genomics (HOPE-Genomics). | Bioinformatics and Genomics, Patient Portal
Hettinger, Aaron Zachary | MedStar Health Research Institute | Context is Critical: Understanding When and Why Electronic Health Record Related Safety Hazards Happen (https://healthit.ahrq.gov/ahrq-funded-projects/context-critical-understanding-when-and-why-electronic-health-record-related) | This project will develop a method to use video captured electronic health record interactions to analyze the context around medication errors, identify design elements that contributed to the errors, and make design recommendations to mitigate those errors. | Electronic Health Record/Electronic Medical Record, Architecture
Holden, Richard | Indiana University-Purdue University at Indianapolis | Power to the Patient: Design and Test of Closed-Loop Interactive IT for Geriatric Heart Failure Self-Care (https://healthit.ahrq.gov/ahrq-funded-projects/power-patient-design-and-test-closed-loop-interactive-it-geriatric-heart) | The goal of this project is to design and test an information technology called Power to the People to support self-care management among older patients with chronic heart failure. | Consumer Health Informatics, Patient-Generated Health Data, Patient Portal
Kazemi, Donna | University of North Carolina Charlotte | mHealth Delivery of a Motivational Intervention to Address Heavy Drinking Among College Students (https://healthit.ahrq.gov/ahrq-funded-projects/mhealth-delivery-motivational-intervention-address-heavy-drinking-among-college) | This project developed and tested a smartphone application of an alcohol intervention for college freshmen and found that it worked as well as a traditional in-person approach. | Consumer Health Informatics, Mobile Phone, Text Messaging, Mobile Device
Kutney-Lee, Ann | University of Pennsylvania | Electronic Health Record Use, Work Environments, and Patient Outcomes (https://healthit.ahrq.gov/ahrq-funded-projects/electronic-health-record-use-work-environments-and-patient-outcomes) | Focusing on the work environment of nurses, this project will study the organizational conditions under which electronic health records function best in hospitals and their potential to improve the outcomes of medical-surgical patients. | Electronic Health Record/Electronic Medical Record
Lee,Joyce | University of Michigan at Ann Arbor | Patient-Centered Data Visualizations for Diabetes (https://healthit.ahrq.gov/ahrq-funded-projects/patient-centered-data-visualizations-diabetes) | This project developed a diabetes data visualization mobile application for adolescents and found that clinical and contextual data provided greater opportunity for self-management and problem solving. | Mobile Device, Remote Patient Monitoring
Leroy, Gondy | University Of Arizona | Enabling Large-Scale Research on Autism Spectrum Disorders Through Automated Processing of EHR Using Natural Language Understanding (https://healthit.ahrq.gov/ahrq-funded-projects/enabling-large-scale-research-autism-spectrum-disorders-through-automated) | This project will design natural language processing algorithms to extract data from free text notes on autism spectrum disorders in electronic health records, and demonstrate the feasibility and usefulness of this approach. | Artificial Intelligence, Machine Learning, Natural Language Processing System
Leung, May May | Hunter College | Intervention INC: Interactive Nutrition Comics for Urban Minority Youth (https://healthit.ahrq.gov/ahrq-funded-projects/intervention-inc-interactive-nutrition-comics-urban-minority-youth) | The research team designed and developed “Invention INC,” an interactive nutrition comic for dietary self-management, focused on reducing childhood obesity risk in urban minority youth. | Mobile Device, Mobile Phone, Consumer Health Informatics
Levin, Scott Ryan | Johns Hopkins University | HopScore: An Electronic Outcomes-Based Emergency Triage System (https://healthit.ahrq.gov/ahrq-funded-projects/hopscore-electronic-outcomes-based-emergency-triage-system) | This project developed and pilot-tested a novel, outcomes-based emergency department triage tool and found that risk stratification and waiting times were improved for some patients. | Clinical Decision Support System, Electronic Health Record/Electronic Medical Record, Machine Learning
Lindquist, Lee A. | Northwestern University | Improving Outpatient Safety of Older Adults Through Electronic Patient Portals (https://healthit.ahrq.gov/ahrq-funded-projects/improving-outpatient-safety-older-adults-through-electronic-patient-portals) | This project evaluated the effects of providing caregivers of older adults proxy access to electronic patient portals and found that information exchange between caregivers and providers increased. | Patient Portal, Secure Messaging
Liss, David T. | Northwestern University | Using Location-Based Smartphone Alerts Within a System of Care Coordination (https://healthit.ahrq.gov/ahrq-funded-projects/using-location-based-smartphone-alerts-within-system-care-coordination) | This project will design and implement a care coordination system using a smartphone application that sends location-based alerts to care managers when high-risk patients receive care at a regional hospital or emergency room. | Mobile Phone, Mobile Device, Geographic Information System
Meguid, Robert A. | University of Colorado, Denver | Surgical Risk Preoperative Assessment System (https://healthit.ahrq.gov/ahrq-funded-projects/surgical-risk-preoperative-assessment-system) | This project developed a patient-centric tool called the Surgical Risk Preoperative Assessment System to estimate the risk of adverse operative outcomes. | Clinical Decision Support System, Machine Learning, Electronic Health Record/Electronic Medical Record
Moore, Susan Louise | Denver Health and Hospital Authority | Engaging Disadvantaged Patients in Sharing Patient-Generated Health Data and Patient-Reported Outcomes through Health Information Technology (https://healthit.ahrq.gov/ahrq-funded-projects/engaging-disadvantaged-patients-sharing-patient-generated-health-data-and) | This study will test the hypothesis that low-income, disadvantaged patients can provide high-quality patient-generated health data and patient-reported outcomes through commercial technologies, and that these data can be used to improve healthcare quality and delivery. | Mobile Device, Mobile Phone, Patient-Generated Health Data
Nahm, Eun-Shim | University of Maryland | A Theory-Based Patient Portal eLearning Program for Older Adults With Chronic Illnesses (https://healthit.ahrq.gov/ahrq-funded-projects/theory-based-patient-portal-elearning-program-older-adults-chronic-illnesses) | This project will optimize and implement a vendor-agnostic eLearning program that supports older adults in using patient portals for their care. | Patient Portal
Ornstein, Steven | Medical University of South Carolina | Learning From Primary Care EHR Exemplars About Health IT Safety (https://healthit.ahrq.gov/ahrq-funded-projects/learning-primary-care-ehr-exemplars-about-health-it-safety) | The study assessed perspectives on electronic health record safety recommendations and found that physicians generally agreed with the recommendations, despite not being familiar with them. | Electronic Health Record/Electronic Medical Record
Pratap, Jayant | Cincinnati Children’s Hospital Medical Center | Using the Electronic Health Record To Identify Children Likely To Suffer Last-Minute Surgery Cancellation (https://healthit.ahrq.gov/ahrq-funded-projects/using-electronic-health-record-identify-children-likely-suffer-last-minute) | This project will apply machine learning against a large data set to develop a model to both understand and predict surgical cancellations on individual pediatric patients at two pediatric surgical sites. | Artificial Intelligence, Electronic Health Record/Electronic Medical Record, Machine Learning
Rangachari, Pavani | Augusta University | Using Social Knowledge Networking (SKN) Technology To Enable Meaningful Use of EHR Technology (https://healthit.ahrq.gov/ahrq-funded-projects/using-social-knowledge-networking-skn-technology-enable-meaningful-use-ehr) | This pilot project implemented a Social Knowledge Networking system and concluded that it supported progress toward meaningful use of medication reconciliation technology in an electronic health record. | Electronic Health Record/Electronic Medical Record, Knowledge System, Social Media
Rao, Goutham | NorthShore University HealthSystem | Improving Diagnosis of Hypertension in Children (IDHC) (https://healthit.ahrq.gov/ahrq-funded-projects/improving-diagnosis-hypertension-children-idhc) | This project developed, implemented, and evaluated a program that includes clinical decision support to improve diagnosis of hypertension in children. | Clinical Decision Support System, Electronic Health Record/Electronic Medical Record
Schnipper, Jeffrey Lawrence | Brigham and Women’s Hospital | Electronic Medication Adherence Reporting and Feedback During Care Transitions (https://healthit.ahrq.gov/ahrq-funded-projects/electronic-medication-adherence-reporting-and-feedback-during-care-transitions) | This project will implement and evaluate a “smart” pillbox given to patients in order to understand its ability to minimize discrepancies in prescribed regimens and to improve patients’ medication adherence after hospital discharge. | Mobile Device, Mobile Phone, Text Messaging
Sherwin, Robert | Wayne State University | Enhancing an EMR-Based Real-Time Sepsis Alert System Performance Through Machine Learning (https://healthit.ahrq.gov/ahrq-funded-projects/enhancing-emr-based-real-time-sepsis-alert-system-performance-through-machine) | This project will use machine learning to enhance an existing sepsis clinical decision support tool to improve the early detection of sepsis. | Artificial Intelligence, Clinical Decision Support System, Machine Learning, Emergency Department Information System
Snyder, Margie E. | Purdue University | Enhancing Clinical Decision Support Applications for Community Pharmacist-Delivered Medication Therapy Management (https://healthit.ahrq.gov/ahrq-funded-projects/enhancing-clinical-decision-support-applications-community-pharmacist-delivered) | This project will formulate evidence-based recommendations for clinical decision support used by community pharmacist delivering medication therapy management. The goal is to reduce medication-related problems and improve health outcomes for chronically ill patients. | Clinical Decision Support System
Turvey, Carolyn* | University of Iowa | Development of a Targeted Patient Portal Intervention to Improve Depression Treatment Adherence, Satisfaction, and Outcomes (https://healthit.ahrq.gov/ahrq-funded-projects/development-targeted-patient-portal-intervention-improve-depression-treatment) | The project will develop a patient portal intervention to increase patient activation and promote collaborative decision making for patients with depression. | Patient Portal
Valdez, Rupa Sheth | University of Virginia | Accessibility and Beyond: Designing Consumer Health IT for Disabled Individuals (https://healthit.ahrq.gov/ahrq-funded-projects/accessibility-and-beyond-designing-consumer-health-it-disabled-individuals) | This project engaged individuals with physical, sensory, and cognitive disabilities to expand upon existing consumer mobile health application design guidance for social networks. | Consumer Health Informatics, Mobile Device, Standards and Classifications
Wernz, Christian | Virginia Commonwealth University | Evidence-based Contingency Planning for Electronic Health Record Downtime (https://healthit.ahrq.gov/ahrq-funded-projects/evidence-based-contingency-planning-electronic-health-record-downtime) | This project assessed the clinical and operational implications of electronic health record downtimes and developed a simulation model to support the creation of effective downtime contingency plans. | Electronic Health Record/Electronic Medical Record, Knowledge System, Clinical Information System
Xie, Anping | Johns Hopkins University | Development of a Clinical Decision Support Tool for Facilitating Naturalistic Decision-Making and Improving Blood Culture Utilization (https://healthit.ahrq.gov/ahrq-funded-projects/development-clinical-decision-support-tool-facilitating-naturalistic-decision) | This project will develop and evaluate an electronic health record-embedded clinical decision support tool that draws upon the strength of analytical and naturalistic decision-making to optimize the use of blood cultures in critically ill children. | Clinical Decision Support System, Electronic Health Record/Electronic Medical Record, Laboratory Information System
Ye, Lichuan | Boston College | A Sleep Promotion Toolkit for Hospitalized Patients (https://healthit.ahrq.gov/ahrq-funded-projects/sleep-promotion-toolkit-hospitalized-patients) | This research developed and pilot-tested a sleep promotion toolkit (SLEEPkit), an application designed to facilitate routine sleep assessment and inform individualized plans for sleep promotion. | Mobile Device
Yen, Po-Yin | Washington University | Development and Evaluation of Sociotechnical Metrics To Inform Health IT Adaptation (https://healthit.ahrq.gov/ahrq-funded-projects/development-and-evaluation-sociotechnical-metrics-inform-health-it-adaptation) | This project will study health information technology adaptation using sociotechnical theory. | Electronic Health Record/Electronic Medical Record
Mentored Clinical Scientist Research Career Development Award (K08)
Principal Investigator | Organization | Project Title | Short Description | Technology
Blecker, Saul B. | New York University School of Medicine | Health Information Technology in Heart Failure Care (https://healthit.ahrq.gov/ahrq-funded-projects/health-information-technology-heart-failure-care) | This project will develop and test a clinical decision support tool to support the delivery of recommended care in hospitalized patients who have heart failure, regardless of the reason for hospitalization. | Artificial Intelligence, Clinical Decision Support System, Machine Learning, Natural Language Processing System, Electronic Health Record/Electronic Medical Record
Gephart, Sheila Maria | University Of Arizona | Clinical Decision Support Optimizing Necrotizing Enterocolitis Prevention Implementation in Neonatal Intensive Care Unit (https://healthit.ahrq.gov/ahrq-funded-projects/clinical-decision-support-optimizing-necrotizing-enterocolitis-prevention) | This project will integrate clinical decision support into providers’ workflow in neonatal intensive care units to deliver evidence-based guidelines for early recognition and prevention of necrotizing enterocolitis, a serious complication threatening the life of fragile premature infants. | Clinical Decision Support System, Electronic Health Record/Electronic Medical Records
Melnick, Edward | Yale University | Clinical Decision Support for Mild Traumatic Brain Injury (https://healthit.ahrq.gov/ahrq-funded-projects/clinical-decision-support-mild-traumatic-brain-injury) | This project developed and piloted a patient-centered clinical decision support tool that was used in emergency department management of minor head injury and found high patient and clinician satisfaction and usability. | Clinical Decision Support System, Mobile Device, Emergency Department Information System
Nanji, Karen C. | Massachusetts General Hospital | Preventing Perioperative Medication Errors and Adverse Drug Events Through the Use of Clinical Decision Support (https://healthit.ahrq.gov/ahrq-funded-projects/preventing-perioperative-medication-errors-and-adverse-drug-events-through-use) | This project will develop a clinical decision support tool for the perioperative setting. | Clinical Decision Support System, Electronic Health Record/Electronic Medical Record
Smith, Angela B. | University of North Carolina Chapel Hill | Developing an Interactive, Patient-Centered mHealth Tool to Enhance Post-Cystectomy Care (https://healthit.ahrq.gov/ahrq-funded-projects/developing-interactive-patient-centered-mhealth-tool-enhance-post-cystectomy) | This project will develop a mobile health tool that will prospectively collect patient-centered outcomes data on key symptoms of postoperative bladder cancer patients. | Internet, Mobile Device, Mobile Phones, Patient-Generated Health Data
Wasson, Lauren | Columbia University Health Sciences | Improving Diagnosis of Cardiovascular Disease in the Emergency Department Using Cognitive Informatics Tools (https://healthit.ahrq.gov/ahrq-funded-projects/improving-diagnosis-cardiovascular-disease-emergency-department-using-cognitive) | This project will develop a patient-based dashboard to improve cognitive hygiene in the emergency department, aiding in the diagnosis of acute coronary syndrome. | Dashboard, Electronic Health Record/Electronic Medical Record
Ancker, Jessica | Weill Medical College of Cornell University | Improving Healthcare Quality with User-Centric Patient Portals (https://healthit.ahrq.gov/ahrq-funded-projects/improving-healthcare-quality-user-centric-patient-portals) | This project studied patient portals, their use in primary care, and the impact of use on chronic conditions, and identified opportunities to improve adoption of patient portals. | Consumer Health Informatics, Patient-Generated Health Data, Patient Portal
Understanding Clinical Information Needs and Health Care Decision Making Processes in the Context of Health IT (R01)
Principal Investigator | Organization | Project Title | Short Description | Technology
Carayon, Pascale | University of Wisconsin - Madison | Health Information Technology-Supported Process for Preventing and Managing Venous Thromboembolism (https://healthit.ahrq.gov/ahrq-funded-projects/health-information-technology-supported-process-preventing-and-managing-venous-thromboembolism) | The purpose of this project is to evaluate the cognitive and teamwork involved in venous thromboembolism prevention and management and to develop design requirements for a clinical decision support tool that supports this collaborative work. | Clinical Decision Support System, Standards and Classifications, Architecture, Clinical Information System
Cohen, Deborah Jill | Oregon Health and Science University | Clinical Information Needs of Community Health Centers for Health Information Technology (https://healthit.ahrq.gov/ahrq-funded-projects/clinical-information-needs-community-health-centers-health-information) | This project will identify the information needs required to ensure effective care coordination for complex patients through extensive ethnographic assessment and interviews, and employ user-centered design methods to rapidly develop and test tools that address these needs. | Electronic Health Record/Electronic Medical Record, Architecture
Gold, Jeffrey Allen | Oregon Health and Science University | Electronic Health Record Solutions for Accurate Reporting of Data on Interprofessional Intensive Care Unit rounds (https://healthit.ahrq.gov/ahrq-funded-projects/electronic-health-record-solutions-accurate-reporting-data-interprofessional) | This project will develop a series of standards for electronic health records to ensure adequate and accurate data communication for care team members in the intensive care environment. | Electronic Health Record/Electronic Medical Record
Gurses, Ayse Pinar | Johns Hopkins University | Care Transitions and Teamwork in Pediatric Trauma: Implications for Health Information Technology Design (https://healthit.ahrq.gov/ahrq-funded-projects/care-transitions-and-teamwork-pediatric-trauma-implications-health-information) | This project seeks to develop an understanding of the cognitive work of clinician teams and family members involved in pediatric trauma care transitions in order to design usable and useful health information technologies. | Electronic Health Record/Electronic Medical Record, Architecture
Harle, Christopher Albert | Indiana University-Purdue University at Indianapolis | Designing User-Centered Decision Support Tools for Chronic Pain in Primary Care (https://healthit.ahrq.gov/ahrq-funded-projects/designing-user-centered-decision-support-tools-chronic-pain-primary-care) | This project will develop decision support tools that integrate with electronic health records to increase the quality and effectiveness of chronic pain care. | Clinical Decision Support System
Hettinger, Aaron Zachary | MedStar Health Research Institute | Cognitive Engineering for Complex Decisionmaking & Problem Solving in Acute Care (https://healthit.ahrq.gov/ahrq-funded-projects/cognitive-engineering-complex-decisionmaking-problem-solving-acute-care) | This project will apply the science of human factors and cognitive engineering to the design of clinical decision support and information technology with the goal of improving patient safety. | Architecture, Standards and Classifications, Emergency Department System, Knowledge System, Clinical Informatics
Koopman, Richelle J. | University of Missouri at Columbia | Optimizing Display of Blood Pressure Data To Support Clinical Decision (https://healthit.ahrq.gov/ahrq-funded-projects/optimizing-display-blood-pressure-data-support-clinical-decision) | This project will determine the optimal display of blood pressure data for patients and their physicians in order to facilitate shared decision making about blood pressure control and treatment. | Clinical Decision Support System, Patient-Generated Health Data, Remote Patient Monitoring
Lavallee, Danielle | University of Washington | Developing Design Principles to Integrate Patient-Reported Outcomes (PROs) Into Clinical Practice Through Health Information Technology: Data, User Experience, and Workflow Requirements for PRO Dashboards (https://healthit.ahrq.gov/ahrq-funded-projects/developing-design-principles-integrate-patient-reported-outcomes-pros-clinical) | This project will develop design principles to enable more effective integration of patient-reported outcomes data into patient care activities through health information technology. | Dashboard
Manojlovich, Milisa | University of Michigan at Ann Arbor | The Effect of Health Information Technology on Health Care Provider Communication (https://healthit.ahrq.gov/ahrq-funded-projects/effect-health-information-technology-health-care-provider-communication) | The purpose of this study is to describe how communication technologies make it easier or more difficult for nurses and physicians to communicate with each other, with a goal of finding ways to support effective communication. | Clinical Documentation, Clinical Messaging, Health Information Exchange, Practice Management System
Melton-Meaux, Genevieve | University of Minnesota, Twin Cities | Discovery and Visualization of New Information from Clinical Reports in the Electronic Health Record (https://healthit.ahrq.gov/ahrq-funded-projects/discovery-and-visualization-new-information-clinical-reports-electronic-health) | The project team developed automated methods for identifying relevant new information versus redundant information in electronic health record clinical notes. | Artificial Intelligence, Clinical Documentation, Electronic Health Record/Electronic Medical Record, Natural Language Processing System
Singh, Hardeep | Baylor College of Medicine | Decision Making and Clinical Work of Test Result Followup in Health Information Technology Settings (https://healthit.ahrq.gov/ahrq-funded-projects/decision-making-and-clinical-work-test-result-followup-health-information) | This project applied a human factors-based framework to understand factors associated with missed test results and found that health information technology is a key barrier to test followup. | Electronic Health Record/Electronic Medical Record
Wetterneck, Tosha Beth | University of Wisconsin - Madison | Understanding Primary Care Teamwork in Context: Implications for Health Information Technology Design (https://healthit.ahrq.gov/ahrq-funded-projects/understanding-primary-care-teamwork-context-implications-health-information) | This project will inform the design of electronic health records to support the cognitive work of primary care clinicians and teams. | Dashboard, Electronic Health Record/Electronic Medical Record, Architecture
Windle, John | University of Nebraska Medical Center | Optimizing the Electronic Health Record for Cardiac Care (https://healthit.ahrq.gov/ahrq-funded-projects/optimizing-electronic-health-record-cardiac-care) | This project will study the usability of electronic health records (EHRs) by cardiac care physicians and nurses to develop a set of best practices in EHR design to inform vendors of the wants and needs of clinical providers. | Electronic Health Record/Electronic Medical Record
Bertoni, Alain | Wake Forest University Health Sciences | Maximizing the Impact of ePHIM in Low-Income, Multiethnic Populations (https://healthit.ahrq.gov/ahrq-funded-projects/maximizing-impact-ephim-low-income-multiethnic-populations) | Using a community-based participatory partnership, this project will delineate the factors that facilitate or limit the use of electronic personal health information management. | Electronic Health Record/Electronic Medical Record, Patient Portal
Jackson, Gretchen P. | Vanderbilt University | Personal Health Information Needs and Practices for Maternal Fetal Care (https://healthit.ahrq.gov/ahrq-funded-projects/personal-health-information-needs-and-practices-maternal-fetal-care) | Women have unique information needs during their pregnancies, ranging from medical questions about pregnancy to logistical concerns about hospital policies. This project is designed to understand these needs, the contexts in which they occur, and the resources used. | Consumer Health Informatics, Patient Portal, Personal Health Record
Matthews, Judith T. | University of Pittsburgh at Pittsburgh | Self-Management via Health Kiosk by Community-Residing Older Adults (https://healthit.ahrq.gov/ahrq-funded-projects/self-management-health-kiosk-community-residing-older-adults) | This project will investigate older adults’ perceptions of, motivations to use, and patterns of using an adaptive, community-based, multiuser health kiosk. | Kiosk, Secure Messaging
Ponto, Kevin | University of Wisconsin - Madison | vizHOME: A Context-Based Health Information Needs Assessment Strategy (https://healthit.ahrq.gov/ahrq-funded-projects/vizhome-context-based-health-information-needs-assessment-strategy) | The purpose of this project is to create a systematic way to understand and measure how household context—such as storage adequacy, lighting, and privacy affordance—influences personal health information management. | Artificial Intelligence, Consumer Health Informatics, Virtual Reality, Remote Patient Monitoring
Pratt, Wanda | University of Washington | Patients as Safeguards: Understanding the Information Needs of Hospitalized Patients (https://healthit.ahrq.gov/ahrq-funded-projects/patients-safeguards-understanding-information-needs-hospitalized-patients) | In an effort to reduce medical errors and adverse events, this project will determine the information needs of hospitalized patients and caregivers, and develop design requirements for a solution that supports communicating safety concerns to providers. | Consumer Health Informatics
Ralston, James D. | Group Health Cooperative | Understanding and Honoring Patients with Multiple Chronic Conditions (https://healthit.ahrq.gov/ahrq-funded-projects/understanding-and-honoring-patients-multiple-chronic-conditions) | This project determined care priorities for patients with multiple chronic conditions based on patient needs, preferences, and capabilities and developed a set of recommendations for patients and providers. | Electronic Health Record/Electronic Medical Record
Safran, Charles | Beth Israel Deaconess Medical Center | InfoSage Information Sharing Across Generation and Environments (https://healthit.ahrq.gov/ahrq-funded-projects/infosage-information-sharing-across-generation-and-environments) | This project will examine the health care information needs and management challenges of older adults and family members involved in their care. | Consumer Health Informatics
Thompson, Hayley S. | Wayne State University | eHealth Activity Among African-American and White Cancer Survivors (https://healthit.ahrq.gov/ahrq-funded-projects/ehealth-activity-among-african-american-and-white-cancer-survivors) | This study focuses on the use of eHealth in cancer survivors and will identify determinants of eHealth activity, provide insight into the role of eHealth in survivors’ overall personal health information management, and establish survivor-centered design principles for optimized eHealth tool development. | Internet, Mobile Device, Consumer Health Informatics, Patient Generated Health Data
Turner, Anne M. | University of Washington | Addressing the Personal Health Information Management Needs of Older Adults (https://healthit.ahrq.gov/ahrq-funded-projects/addressing-personal-health-information-management-needs-older-adults) | This project will examine the health information needs of older adults to inform the design of systems to support their health and independence. | Consumer Health Informatics
Vawdrey, David Kent | Columbia University | Addressing Hospital Patient Information Needs Using a Personal Health Record Portal (https://healthit.ahrq.gov/ahrq-funded-projects/addressing-hospital-patient-information-needs-using-personal-health-record) | This project evaluated the impact of an inpatient portal used by cardiac patients and found that patients using the portal had a lower 30-day hospital readmission rate. | Consumer Health Informatics, Mobile Device, Patient Portal, Personal Health Record
AHRQ Patient Centered Outcomes Research (PCOR) Pathway to Independence Award (K99/R00)
Principal Investigator | Organization | Project Title | Short Description | Technology
Lyles, Courtney | University of California, San Francisco | Engaging Diverse Patients in Using an Online Patient Portal (https://healthit.ahrq.gov/ahrq-funded-projects/engaging-diverse-patients-using-online-patient-portal) | The goal of this project is to improve chronic illness care for ethnically and racially diverse patients using a patient portal. | Patient Portal
AHRQ Patient Centered Outcomes Research Clinical Decision Support Learning Network (U18)
Principal Investigator | Organization | Project Title | Short Description | Technology
Blumenfeld, Barry H. | RTI International | Patient-Centered Outcomes Research Clinical Decision Support Learning Network (https://healthit.ahrq.gov/ahrq-funded-projects/patient-centered-outcomes-research-clinical-decision-support-learning-network) | The Patient-Centered Outcomes Research Clinical Decision Support Learning Network (PCOR CDS-LN) will explore the facilitators and barriers to the use of PCOR findings in CDS software and will formulate recommendations for ways to increase the uptake and use of CDS incorporating PCOR findings. | Clinical Decision Support System
Utilizing Health Information Technology to Scale and Spread Successful Practice Models Using Patient reported Outcomes (R18)
Principal Investigator | Organization | Project Title | Short Description | Technology
Jariwala, Sunit* | Albert Einstein College of Medicine | Adapting, Scaling, and Spreading an Algorithmic Asthma Mobile Intervention to Promote Patient-Reported Outcomes Within Primary Care Settings (https://healthit.ahrq.gov/ahrq-funded-projects/adapting-scaling-and-spreading-algorithmic-asthma-mobile-intervention-promote) | This project will adapt and evaluate a mobile health application to improve patient-reported asthma outcomes in New York. | Electronic Health Record/Electronic Medical Record, Mobile Device, Patient Generated Health Data
Lenert, Leslie A.* | Medical University of South Carolina | EHR-based Screening and Intervention for Intimate Partner Violence (https://healthit.ahrq.gov/ahrq-funded-projects/ehr-based-screening-and-intervention-intimate-partner-violence) | This project will design, implement, and evaluate a comprehensive set of tools in an electronic health record (EHR) to support improved intimate partner violence care. | Clinical Decision Support System, Electronic Health Record/Electronic Medical Record, Public Health Informatics, Patient Generated Health Data, Telemedicine System
Penedo, Frank* | Northwestern University | Expansion, Implementation, and Evaluation of Electronic Health Record-Integrated Patient-Reported Symptom Screening in a Comprehensive Cancer Center (https://healthit.ahrq.gov/ahrq-funded-projects/expansion-implementation-evaluation-electronic-health-record-integrated-patient) | This project will expand, implement, and evaluate the use of a cancer screening platform, the Oncology Symptom Screening Initiative (OSSI), to improve psychosocial screening of cancer patients. | Patient Portal, Patient Generated Health Data, Health Information Exchange, Architecture, Electronic Health Record/Electronic Medical Record
Rudin, Robert Samuel* | RAND Corporation | Integrating Patient-Reported Outcomes into Routine Primary Care: Monitoring Asthma Between Visits (https://healthit.ahrq.gov/ahrq-funded-projects/integrating-patient-reported-outcomes-routine-primary-care-monitoring-asthma) | The project is adapting and scaling a technology-enabled practice model for asthma in a primary care setting, then evaluating its impact on patient-reported quality of life and utilization. | Dashboard, Mobile Phone, Text Messaging, Patient Generated Health Data
Yazdany, Jinoos* | University of California, San Francisco | Rheumatology Informatics System for Effectiveness Patient-Reported Outcome (RISE PRO) Dissemination Project (https://healthit.ahrq.gov/ahrq-funded-projects/rheumatology-informatics-system-effectiveness-patient-reported-outcome-rise-pro) | This project will create and evaluate a learning network to expand the use of the Rheumatology Informatics System for Effectiveness (RISE) registry for patient-reported outcomes on rheumatoid arthritis. | Artificial Intelligence, Dashboard, Natural Language Processing System, Registry, Patient Generated Health Data, Database, Patient Portal
Health Information Technology (IT) to Improve Health Care Quality and Outcomes (R21)
Principal Investigator | Organization | Project Title | Short Description | Technology
Friedman, Charles* | University of Michigan at Ann Arbor | Achieving Individualized Precision Prevention (IPP) through Scalable Infrastructure Employing the USPSTF Recommendations in Computable Form (https://healthit.ahrq.gov/ahrq-funded-projects/achieving-individualized-precision-prevention-ipp-through-scalable) | This project will use Learning Health System methods to systematically apply U.S. Preventive Services Task Force’s evidence-based recommendations with the goal of advancing individualized precision prevention. | Machine Learning, Mobile Device, Electronic Health Record/Electronic Medical Record, Knowledge System
Lakes, Kimberley* | University of California Riverside | The CoolCraig App: Promoting Health by Improving Self-Regulation in Adolescents with ADHD (https://healthit.ahrq.gov/ahrq-funded-projects/coolcraig-app-promoting-health-improving-self-regulation-adolescents-adhd) | This project will develop and evaluate CoolCraig, a wearable and connected system combining a fitness tracker, mobile phone application, and web portal that will deliver, reinforce, and sustain treatment for adolescents with attention deficit hyperactivity disorder. | Mobile Device, Patient Portal
Ruggiano, Nicole* | University of Alabama in Tuscaloosa | Examining the Clinical Workflow and Outcomes of Integrating Health Information Technology to Educate and Support Dementia Caregivers (https://healthit.ahrq.gov/ahrq-funded-projects/examining-clinical-workflow-and-outcomes-integrating-health-information) | This project will evaluate the integration into clinical care of CareHeroes, an application to support caregivers of those with Alzheimer’s disease. | Mobile Device, Mobile Phone, Patient-Generated Health Data, internet, Architecture
Wallace, Andrea* | University of Utah | From Emergency to Community: Implementing a Social Needs Assessment and Referral Infrastructure Using Health Information Technology (https://healthit.ahrq.gov/ahrq-funded-projects/emergency-community-implementing-social-needs-assessment-and-referral) | This project will implement a social needs assessment in an emergency department and evaluate its impact on health outcomes. | Electronic Health Record/Electronic Medical Record
Developing New Clinical Decision Support to Disseminate and Implement Evidence Based Research Findings (R18)
Principal Investigator | Organization | Project Title | Short Description | Technology
Gong, Michelle* | Albert Einstein College of Medicine | TREAT ECARDS: Translating Evidence into Action: Electronic Clinical Decision Support in ARDS (https://healthit.ahrq.gov/ahrq-funded-projects/treat-ecards-translating-evidence-action-electronic-clinical-decision-support) | This project will develop and evaluate an electronic clinical decision support tool for care of patients with Acute Respiratory Distress Syndrome. | Clinical Decision Support System, Dashboard, Machine Learning, Natural Language Processing System
Implementation and Evaluation of New Health Information Technology (IT) Strategies for Collecting
Principal Investigator | Organization | Project Title | Short Description | Technology
Kalenderian, Elsbeth* | University of California, San Francisco | Optimizing Acute Post-Operative Dental Pain Management Using New Health Information Technology (https://healthit.ahrq.gov/ahrq-funded-projects/optimizing-acute-post-operative-dental-pain-management-using-new-hit) | This project will use mobile health technology to collect patient-reported outcomes after dental procedures to optimize the quality of acute post-operative dental pain management. | Mobile Device, Patient-Generated Health Data
Laiteerapong, Neda* | University of Chicago | Patient Outcomes Reporting for Timely Assessments of Life with Depression: PORTAL-Depression (https://healthit.ahrq.gov/ahrq-funded-projects/patient-outcomes-reporting-timely-assessments-life-depression-portal-depression) | This project will integrate the Computerized Adaptive Test for Mental Health into an electronic health record and evaluate the effectiveness of collecting depression symptoms with a patient portal. | Patient-Generated Health Data, Patient Portal
AHRQ Conference Grant Program (R13)
Principal Investigator | Organization | Project Title | Short Description | Technology
O’Brien, Matthew James* | Northwestern University | Prevent Diabetes Mellitus (PreDM) Clinical Decision Support Intervention in Community Health Centers (https://healthit.ahrq.gov/ahrq-funded-projects/prevent-diabetes-mellitus-predm-clinical-decision-support-intervention) | This project will develop and evaluate the impact of the Prevent Diabetes Mellitus Clinical Decision Support on clinical outcomes, healthcare process measures, and associated costs. | Clinical Decision Support System, Dashboard
Agarwal, Ritu* | University of Maryland | Annual Conference on Health Information Technology & Analytics (CHITA) (https://healthit.ahrq.gov/ahrq-funded-projects/annual-conference-health-information-technology-analytics-chita) | The central goal of the annual Conference on Health IT & Analytics is to develop a health information technology and analytics (HIT+A) research agenda that supports national efforts to create a learning health system that produces evidence to make health care safer, of higher quality, more accessible, equitable, and affordable. | Bioinformatics and Genomics, Clinical Informatics, Data, Machine Learning
Contracts
Principal Investigator | Organization | Project Title | Short Description | Technology
Loube, Robyn* | Sensis, Inc. | AHRQ Patient-Reported Outcome Challenge Competition Support (https://healthit.ahrq.gov/ahrq-funded-projects/ahrq-patient-reported-outcome-challenge-competition-support) | This contract provided the administration and management of the Agency for Healthcare Research and Quality’s “Step Up App Challenge: Advancing Care Through Patient Self-Assessments.” | Consumer Health Informatics, Mobile Device
Miller, Kristen, Hettinger, Aaron Zachary* | MedStar Health Research Institute | Quantifying Efficiencies Gained through Shareable Clinical Decision Support Resources (https://healthit.ahrq.gov/ahrq-funded-projects/quantifying-efficiencies-gained-through-shareable-clinical-decision-support) | This research will evaluate the lifecycle of clinical decision support (CDS), as currently implemented at most health systems, against a future CDS state that incorporates the use of shareable CDS resources created using the Agency for Healthcare Research and Quality’s CDS Connect tools. | Clinical Decision Support System, Knowledge System
Wesley, Deliya, Ratwani, Raj M.* | MedStar Health Research Institute | Advancing the Collection and Use of Patient-Reported Outcomes through Health Information Technology (https://healthit.ahrq.gov/ahrq-funded-projects/advancing-collection-and-use-patient-reported-outcomes-through-health) | This research will support development and testing of technical tools for use within electronic health records or other systems to collect patient-reported outcomes for clinical use and research. | Consumer Health Informatics, Mobile Device, Patient-Generated Health Data
Sebastian, Sharon | The MITRE Corporation* | Patient-Centered Outcomes Research Clinical Decision Support Prototype Development and Dissemination (https://healthit.ahrq.gov/ahrq-funded-projects/patient-centered-outcomes-research-clinical-decision-support-prototype) | The goal of this project is to generate a systematic and replicable process for transforming evidence-based research findings, including findings from patient-centered outcomes research, into shareable clinical decision support (CDS) standards and a publicly available CDS prototype. | Clinical Decision Support System, Standards and Classifications
Research Centers in Primary Care Practice Based Research and Learning (P30)
Principal Investigator | Organization | Project Title | Short Description | Technology
Fiks, Alexander | American Academy of Pediatrics | National Center for Pediatric Practice Based Research and Learning (https://healthit.ahrq.gov/ahrq-funded-projects/national-center-pediatric-practice-based-research-and-learning) | This project will establish the Center for Pediatric Practice Research and Learning (C-PRL). This Center will link existing pediatric practice-based research networks to develop evidence-based practices and improve child health outcomes. | Electronic Health Record/Electronic Medical Record, Database