# V CLOSING

In 2018, AHRQ-funded research continued to generate innovative tools and findings in such priority areas as improving whole-person care and patient safety, disseminating evidence-based clinical decision support, and supporting clinicians’ work. The AHRQ Health IT program has an ongoing commitment to support research to understand how health IT can positively affect the quality and safety of healthcare. Visit the AHRQ Health IT website at https://healthit.ahrq.gov/ to learn about funding opportunities (https://healthit.ahrq.gov/ahrq-health-it-funding-opportunities), read more about current research (https://healthit.ahrq.gov/ahrq-funded-projects), and learn about the findings and impact (https://healthit.ahrq.gov/program-overview/success-stories) of the funded work. You will also find information about program-sponsored events (https://healthit.ahrq.gov/national-webinars) and health IT tools and resources (https://healthit.ahrq.gov/health-it-tools-and-resources).