# IV RESEARCH DISSEMINATION

Dissemination of key research findings from the Health IT-funded work is critical to knowledge transfer and replication of successful health IT strategies that impact patient safety, optimize EHR design, and reduce provider burden.

The Health IT-funded researchers publicize and disseminate their research findings in many ways, such as publishing in peer-reviewed journals and presenting at health- and IT-focused conferences, as well as on AHRQ web conferences.

## A Reaching the Research Community Through Web Conferences

AHRQ convenes web-based conferences to showcase recent health IT research developments and further the dialogue on future research. In 2018, AHRQ convened two national web conferences where key findings and impacts from the research were presented. Both webinars were accredited by the Professional Education Services Group to help further dissemination. Over 900 participants attended the conferences.

### Reducing Provider Burden Through Better Health IT Design (https://healthit.ahrq.gov/national-webinars/reducing-provider-burden-through-better-health-it-design)

On Thursday, January 25, 2018, AHRQ hosted a web conference about the impact of health IT design on provider burden. Provider burnout is rising and EHR use is cited as one of the top reported stressors for providers. Poor EHR design can increase provider burden, and AHRQ is supporting research to alleviate provider burden as it relates to health IT design and use, including clinical workflow, physician-patient communication, cognitive load, and user satisfaction. The following presenters discussed their research on optimal design of EHRs to support clinical workflow: Dr. Pascale Carayon from the University of Wisconsin Madison College of Engineering, Dr. Zia Agha from West Health, and Dr. Lukasz Mazur from the University of North Carolina Chapel Hill School of Medicine. A brief summary of research goals and key findings from the researchers presentations are provided below:

- Dr. Pascale Carayon’s research on health IT for venous thromboembolism (VTE) used 11 case studies and a participatory approach to identify design considerations for health IT to support the process of VTE prophylaxis. Following a sociotechnical approach, her research identified 13 categories of design considerations to be incorporated into a health IT system that supports the process of VTE prophylaxis, including the patient’s journey, clinical appropriateness, role clarity among clinical team members, organizational culture, workload, and technology access.
- Dr. Zia Agha’s research quantified EHR usability to improve clinical workflow with regard to cognitive workload and clinician-patient communication. Data were collected with video recordings of patient visits, usability software that tracked how clinicians use the EHR, and a clinician survey. Findings indicate that the EHR user interface imposed very high work burden on clinicians, and provider perception of workload is influenced by the environment and their relationship with the patient.
- Dr. Lukasz Mazur’s research assessed the impact of an EHR that was enhanced for monitoring critical abnormal test results. A randomized controlled trial conducted using test cases in a laboratory environment suggest that the enhanced EHR contributed to improvements in clinical performance and physiological workload. The research concluded that policies and guidelines are required to improve the usability of EHRs to help ensure optimal clinical performance.

Impact: At the culmination of the web conference, participants were equipped with knowledge and approaches to: 1) identify cognitive and teamwork aspects in VTE prophylaxis and sociotechnical system design requirements to support teamwork; 2) assess EHR usability, clinical work flow, cognitive workload, and provider-patient communication; and 3) assess provider mental workload and performance with regard to EHR usability. The conference was attended by 522 participants.

### How Health IT Can Improve Medication Management (https://healthit.ahrq.gov/national-webinars/role-health-it-improve-medication-management)

On September 13, 2018, AHRQ convened a national web conference focused on the use of health IT to improve medication monitoring, adherence, and medication therapy management for patients with complex conditions. As people are living longer, many individuals have multiple chronic conditions that require accordingly complex medication management. The following presenters discussed their research on strategies to improve medication management: Dr. Karen Farris from the University of Michigan College of Pharmacy, Dr. Jeffrey Schnipper from Brigham and Women's Hospital and Harvard Medical School, and Dr. Margie Snyder from Purdue University College of Pharmacy. A brief summary of research goals and key findings from the researchers presentations are provided below:

- Dr. Karen Farris’s research used AI to automatically adapt text messages about blood pressure medication adherence to patients’ medication-taking behaviors. A randomized controlled trial found that individuals using the AI tool reported improvements in medication adherence 3 months into the trial.
- Dr. Jeffrey Schnipper’s research tested a novel electronic pillbox that issued medication reminders and shared adherence data with the patient’s provider. A randomized controlled trial was conducted among patients taking five or more medications for chronic conditions at the time of hospital discharge. The study team worked with providers and pharmacists to overcome barriers to refilling medications by using blister packs that were compatible with the pillbox, and worked with patients to help them identify locations in their homes where Wifi connectivity was adequate to transfer data from the pillbox.
- Dr. Margie Snyder’s research investigated the alignment of CDS with established human factors principles and assessed the usability and usefulness of CDS for community pharmacists for patient care. Findings from the study are forthcoming.

Impact: By the end of the conference, participants were able to: 1) explain the benefits and challenges of using AI for generating text messages to support medication adherence; 2) discuss evaluation of a pillbox used by patients during transitions in care; and 3) describe human factors, usability, and utility of a CDS for community pharmacists. The conference was attended by 402 participants.

## B Reaching Diverse Audiences Through Conference Proceedings

AHRQ-funded researchers presented their work at a variety of health IT, medical, and other key conferences, such as the Annual Symposium for the American Medical Informatics Association (AMIA), AcademyHealth’s Annual Research Meeting, the Human Factors and Ergonomics in Health Care Annual Symposium, International Conference on Healthcare Informatics, and the Health Information Management Systems Society’s Global Conference and Exhibition.

At the 2018 AMIA Annual Symposium alone, AHRQ Health IT-funded research was highlighted in:

– 11 oral presentations
– 4 panel presentations
– 4 posters
– 2 systems demonstrations
– 2 instructional workshops

Table 4 AHRQ-Funded Research at the 2018 AMIA Annual Symposium

Investigator Name | AHRQ Research Profile | AMIA Title | Type
Abraham, Joanna | An Etiology for Medication Ordering Errors in Computerized Provider Order Entry Systems (https://healthit.ahrq.gov/ahrq-funded-projects/etiology-medication-ordering-errors-computerized-provider-order-entry-systems) | Clinician Perspectives on Duplicate Medication Ordering Errors (https://symposium2018.zerista.com/event/member/508247) | Oral Presentation
Adelman, Jason; Patel, Vimla | Develop and Validate Health IT Safety Measures To Capture Violations of the Five Rights of Medication Safety; (https://healthit.ahrq.gov/ahrq-funded-projects/develop-and-validate-health-it-safety-measures-capture-violations-five-rights); Assess Risk of Wrong-Patient Errors in an EMR That Allows Multiple Records Open; (https://healthit.ahrq.gov/ahrq-funded-projects/assess-risk-wrong-patient-errors-emr-allows-multiple-records-open); Impact of Meaningful Use on Clinical Workflow in Emergency Departments (https://healthit.ahrq.gov/ahrq-funded-projects/impact-meaningful-use-clinical-workflow-emergency-departments) | Panel - EHR Log Data: An Untapped Health Data Goldmine for Clinical Informatics Research? (https://symposium2018.zerista.com/event/member/508359) | Panel Presentation
Blumenfeld, Barry | Patient-Centered Outcomes Research Clinical Decision Support Learning Network (https://healthit.ahrq.gov/ahrq-funded-projects/patient-centered-outcomes-research-clinical-decision-support-learning-network) | From Evidence to Action: Enabling Opioid Pain Management Guidelines Through Patient-Centered Clinical Decision Support (https://symposium2018.zerista.com/event/member/508668) | Panel Presentation
Dixon, Brian | Improving Population Health Through Enhanced Targeted Regional Decision Support (https://healthit.ahrq.gov/ahrq-funded-projects/improving-population-health-through-enhanced-targeted-regional-decision-support) | Improving Population Health Reporting through Information Exchange Supported Decision Support: A Controlled Before-and-After Trial (https://symposium2018.zerista.com/event/member/508402) | Oral presentation
Harle, Christopher | Designing User-Centered Decision Support Tools for Chronic Pain in Primary Care (https://healthit.ahrq.gov/ahrq-funded-projects/designing-user-centered-decision-support-tools-chronic-pain-primary-care) | Information Needs and Requirements for Decision Support in Primary Care: An Analysis of Chronic Pain Care (https://symposium2018.zerista.com/event/member/507978) | Oral Presentation
Harle, Christopher | Designing User-Centered Decision Support Tools for Chronic Pain in Primary Care (https://healthit.ahrq.gov/ahrq-funded-projects/designing-user-centered-decision-support-tools-chronic-pain-primary-care) | Panel - Informatics Needs and Solutions to Support Safe Opioid Prescribing and Effective Pain Care (https://symposium2018.zerista.com/event/member/508083) | Panel Presentation
Jackson, Gretchen | Personal Health Information Needs and Practices for Maternal Fetal Care (https://healthit.ahrq.gov/ahrq-funded-projects/personal-health-information-needs-and-practices-maternal-fetal-care) | Communication Technology Use and Preferences for Pregnant Women and Their Caregivers (https://symposium2018.zerista.com/event/member/508267) | Oral presentation
LaVallee, Danielle | Developing Design Principles to Integrate Patient-Reported Outcomes (PROs) Into Clinical Practice Through Health Information Technology: Data, User Experience, and Workflow Requirements for PRO Dashboards (https://healthit.ahrq.gov/ahrq-funded-projects/developing-design-principles-integrate-patient-reported-outcomes-pros-clinical) | Provider Perspectives of Integrating Electronic Patient-Reported Outcomes into Clinical Practice Workflow (https://symposium2018.zerista.com/event/member/508936) | Poster
Leroy, Gondy | Enabling Large-Scale Research on Autism Spectrum Disorders Through Automated Processing of EHR Using Natural Language Understanding (https://healthit.ahrq.gov/ahrq-funded-projects/enabling-large-scale-research-autism-spectrum-disorders-through-automated) | Optimizing Corpus Creation for Training Word Embedding in Low Resource Domains: A Case Study in Autism Spectrum Disorder (ASD) (https://symposium2018.zerista.com/event/member/508386) | Oral Presentation
Moesel, Chris | Patient-Centered Outcomes Research Clinical Decision Support Prototype Development and Dissemination (https://healthit.ahrq.gov/ahrq-funded-projects/patient-centered-outcomes-research-clinical-decision-support-prototype) | Pain Management Summary: A SMART on FHIR Dashboard for Managing Pain (https://symposium2018.zerista.com/event/member/526116) | Showcase - Featured Presentation
Pratt, Wanda | Patients as Safeguards: Understanding the Information Needs of Hospitalized Patients (https://healthit.ahrq.gov/ahrq-funded-projects/patients-safeguards-understanding-information-needs-hospitalized-patients) | Must We Bust the Trust?: Understanding How the Clinician-Patient Relationship Influences Patient Engagement in Safety (https://symposium2018.zerista.com/event/member/508179) | Oral presentation
Pratt, Wanda | Patients as Safeguards: Understanding the Information Needs of Hospitalized Patients (https://healthit.ahrq.gov/ahrq-funded-projects/patients-safeguards-understanding-information-needs-hospitalized-patients) | Exploring the Design of an Inpatient Peer Support Tool: Views of Adult Patients (https://symposium2018.zerista.com/event/member/508173) | Oral presentation
Pratt, Wanda | Patients as Safeguards: Understanding the Information Needs of Hospitalized Patients (https://healthit.ahrq.gov/ahrq-funded-projects/patients-safeguards-understanding-information-needs-hospitalized-patients) | Designs to support informed hospitalized patients (https://symposium2018.zerista.com/event/member/509122) | Poster
Pratt, Wanda | Patients as Safeguards: Understanding the Information Needs of Hospitalized Patients (https://healthit.ahrq.gov/ahrq-funded-projects/patients-safeguards-understanding-information-needs-hospitalized-patients) | Is an Emoji Worth A Thousand Words? Pediatric Inpatient Perspectives on Pictorial Modes of Emotional Subtext in Electronic Health Communication (https://symposium2018.zerista.com/event/member/508957) | Poster
Safran, Charles | InfoSage Information Sharing Across Generation and Environments (https://healthit.ahrq.gov/ahrq-funded-projects/infosage-information-sharing-across-generation-and-environments) | InfoSAGE: Supporting Elders and Families through Online Family Networks (https://symposium2018.zerista.com/event/member/508268) | Oral presentation
Schnall, Rebecca | The Wise App Trial for Improving Health Outcomes in PLWH (https://healthit.ahrq.gov/ahrq-funded-projects/wise-app-trial-improving-health-outcomes-plwh) | Usability and Acceptability of the mLab App for Promoting the Uptake of HIV Testing (https://symposium2018.zerista.com/event/member/509283) | Poster
Schnall, Rebecca | The Wise App Trial for Improving Health Outcomes in PLWH (https://healthit.ahrq.gov/ahrq-funded-projects/wise-app-trial-improving-health-outcomes-plwh) | Panel - Usability Testing Methods for mHealth Apps Designed for Disadvantaged End-users (https://symposium2018.zerista.com/event/member/507936) | Panel Presentation
Vawdrey, David | Addressing Hospital Patient Information Needs Using a Personal Health Record Portal (https://healthit.ahrq.gov/ahrq-funded-projects/addressing-hospital-patient-information-needs-using-personal-health-record) | Engaging Hospitalized Patients with Personalized Health Information: A Randomized Trial of an Acute Care Patient Portal (https://symposium2018.zerista.com/event/member/508253) | Oral presentation
Vawdrey, David | Addressing Hospital Patient Information Needs Using a Personal Health Record Portal (https://healthit.ahrq.gov/ahrq-funded-projects/addressing-hospital-patient-information-needs-using-personal-health-record) | Providers’ Perspectives on Sharing Health Information through Acute Care Patient Portals (https://symposium2018.zerista.com/event/member/508264) | Oral presentation
Vawdrey, David | Addressing Hospital Patient Information Needs Using a Personal Health Record Portal (https://healthit.ahrq.gov/ahrq-funded-projects/addressing-hospital-patient-information-needs-using-personal-health-record) | Low Screening Rates for Diabetes Mellitus Among Family Members of Affected Relatives (https://symposium2018.zerista.com/event/member/508394) | Oral Presentation

### 2018 AMIA Year in Review.

A special livestreaming event held during the 2018 AMIA Annual Symposium featured the year’s most noteworthy publications. This popular Biomedical and Health Informatics Year in Review session is informed by AMIA’s Working Groups, who identify papers from over 90 domains, representing the most influential biomedical and health informatics work published. It is intended to help biomedical and health informatics professionals stay current with the most “relevant, interesting, or innovative” papers of the year. Presented by James Cimino, MD, FACMI, FAMIA, of the Informatics Institute at the University of Alabama at Birmingham, many of the 67 papers reviewed at the 2018 Symposium were authored by AHRQ-funded health IT researchers. Papers from 45 of the domains were presented, including the following AHRQ-funded health IT research.

#### Patient Engagement Research

Dr. Anuj Dalal’s formative research (https://pubmed.ncbi.nlm.nih.gov/28633483/) on identifying critical components for developing patient portals for use in the acute care setting and during transitions of care was highlighted. As hospitalizations have become increasingly shorter, more recovery takes place in the home, resulting in greater information burden and decision-making responsibilities on patients and their caregivers. To support patients and their caregivers with care transitions and post-discharge responsibilities, innovative information and communication tools will be critical to the delivery of safe, high-quality, accessible care. The authors held a patient care portal workshop with 71 attendees from over 30 institutions to discuss a sociotechnical and evaluation research agenda for the use of informatics to support patients and care coordination after discharge. The following areas were identified to be addressed: interoperability standards; privacy and security issues, including remote access and proxies; user-centered design to support complex data and communication; implementation factors such as adoption, cost, and technical support; data and content knowledge management in the EHR; CDS to avoid errors; and measurement standards to support formative assessments. Using these components, the authors suggest that increasing the use of patient portals in the acute care setting and during transitions of care will improve patient engagement and empowerment, and positively affect quality and safety.

#### Clinical Information Systems and Data Capture Research

It common for clinicians to write patient notes well after a patient visit, even hours later, including into the evenings and on weekends. Dr. Thomas Payne’s research (https://www.ncbi.nlm.nih.gov/pubmed/29233669) looked at the use of mobile phone transcription and its impact on when notes were completed and the quality of those notes. This system allows clinicians to dictate notes while they are with patients or walking around. The notes are sent to a secure server, where they are transcribed using NLP and made available for later review, editing, and a signature. Availability is within 5 minutes, which i s a significant improvement over traditional dictation methods. During the 2018 AMIA Year in Review session, Dr. Payne was featured in a video clip dictating notes for a patient encounter that he later retrieved from his inbox. The researchers evaluated the amount of time providers spent after midnight on their clinical notes and found that using mobile phone transcription reduced the amount of time compared with traditional dictation. Additionally, the dictated notes generated with the tool had more new information and far less old text carried forward.

#### Research Reviews

Dr. Richard Holden and his colleagues are researching the use of health IT to inform and support self-management of congestive heart failure. The AMIA Year in Review session highlighted his systematic review (https://pubmed.ncbi.nlm.nih.gov/29233669/) on the use of smartphone apps to change health status and behavior of patients. The reviewed studies had samples of up to 171 individuals, representing those with bipolar disorder, schizophrenia, and depression; older adults; and the general population. Numerous benefits to patients were found, including ability to detect changes in health status and behavior, and an increase in accountability of users. Challenges identified were related to the technology implemented, methods used, and privacy concerns.

#### Consumer Informatics Research

Called by Dr. Cimino “one of the best papers in the AMIA proceedings last year,” this paper (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5977701), co-authored by Dr. Gretchen Jackson, examined factors that influenced information seeking by pregnant patients and their caregivers. The authors found that those with a strong belief in the power of luck, as well as those who believe others are in control, sought information less frequently than their counterparts. When there are “powerful others” and luck, individuals do not see the point in looking for additional information on their care.

A second paper (https://pmc.ncbi.nlm.nih.gov/articles/PMC5977594/) highlighted in this domain was authored by Dr. David Vawdrey, who is researching use of patient portals by inpatients. Recognizing a gap in research, he and others evaluated the impact of sharing clinical notes with hospitalized patients. Ten inpatients were given access to an acute care portal and interviewed for their perspectives around that access to their clinical information. Benefits reported included improved access to information, better understanding of their conditions, and greater appreciation for their providers. Four patients reported changing a health behavior, and two reported the possible prevention of medical errors due to the portal. Usage logs indicated that patients accessed the notes feature of the portal more frequently and for a longer duration than other portal features. Contrary to expectations, an increase in patient anxiety was not found, with the researchers theorizing that access to information reduces the uncertainty and the disempowerment commonly felt by hospitalized patients. The authors concluded that their results should encourage providers to be open-minded about patient access to inpatient notes.

#### Evaluation: Iťs About Methods Domain

Dr. Rebecca Schnall’s AHRQ Health IT-funded research evaluated the use of a mobile Video Information Provider (mVIP), a mobile app targeted to those with HIV. In this paper (https://pubmed.ncbi.nlm.nih.gov/30145317/) she and her colleagues describe a usability evaluation based on the Health IT Usability Evaluation Model (Health-ITUEM), with mVIP used as a case study. The authors described the application of user-centered design reverse card sorting, in which end users sorted features by perceived importance. In the usability lab, a think-aloud protocol with eye tracking heuristic evaluation was completed. Usability of mVIP in real-life situations was evaluated by surveys and interviews. Dr. Cimino described the project as a “nice start-to-finish evaluation.”

## C AHRQ-Funded Researchers Disseminate in High-Impact Journals

In 2018, AHRQ-funded researchers published over 100 research articles in peer-reviewed journals and book chapters, including the following:

### Development and Dissemination of a Novel Quality Improvement Framework to Improve Care for Children in the ICU (https://pubmed.ncbi.nlm.nih.gov/30584639/)

Dr. Anping Xie and colleagues developed and implemented a quality improvement framework to reduce unnecessary blood culture testing for critically ill children in the intensive care unit (ICU). A five-part improvement framework was implemented in three pediatric ICUs and included: 1) a work system assessment conducted during an initial site visit, 2) identification of multidisciplinary stakeholders and a project champion, 3) collection and sharing of blood culture data, 4) adaptation of clinician support tools by each unit, and 5) communication and analysis of progress throughout the implementation process. Across the three units, blood culture rates significantly decreased by 32 percent, and the rate of cultures drawn from central venous catheters decreased by 51 percent. Different approaches were followed at the three units including the identity (i.e., staff role) and involvement of the champion, adaption of clinical tools, and the monitoring and communication of progress.

Search the AHRQ Health IT Projects Publication Database (https://healthit.ahrq.gov/health-it-tools-and-resources/ahrq-digital-healthcare-research-publications-database-search), created to further disseminate work of the funded research, to find other research results!

### Use of a mHealth App Can Reduce College Students Hazardous Drinking. (https://www.ncbi.nlm.nih.gov/pubmed/30407059)

Researcher Dr. Donna Kazemi and her colleagues developed a smartphone app, “SmarTrek,” designed to reduce risky alcohol use in college students. SmarTrek includes eight components that address alcohol use, including interactive games, a feature around blood alcohol content, a daily log, a virtual coach, a “My Strategies” section, the ability to receive personalized feedback, and a resources section. The app’s interactive components, including text messages, incorporated motivational interviewing to facilitate behavior change and ecological momentary interventions (EMI). EMI uses technology to send information to an individual during risky behavior when there is the greater opportunity to promote healthy behaviors. The investigators found 90 percent of participants thought that the app was easy to use, provided useful information, and had a positive effect on reducing their drinking.

### Understanding How Physicians Help Patients Deal with Chronic Pain (https://pmc.ncbi.nlm.nih.gov/articles/PMC6398613/)

In the United States, the complexities of caring for patients with chronic pain are exacerbated by individual and public health risks associated with commonly used opioid analgesics. Chronic pain leads to reduced quality of life for patients and strains health systems in the Nation. Dr. Christopher Harle and his team at Indiana University–Purdue University, Indianapolis (IUPUI), are developing EHR-integrated decision support tools with the goal of increasing the quality and effectiveness of chronic pain care. To help inform their work, the team interviewed 10 primary care clinicians about 30 patients with chronic pain. They identified several patient, social/environmental, and clinician factors that influence clinicians’ assessment of their patients to determine a pain management plan. Significant ambiguity and uncertainty in clinical pain management decision making was identified. Therefore, interventions to improve pain care should focus on providing context of clinical evidence rather than providing clinicians with decontextualized and/or algorithm-based decision rules.

#### AHRQ Health IT-funded research featured in Health Affairs patient safety issue.

The November 2018 issue of Health Affairs, “Patient Safety,” includes a comprehensive look at the best and latest patient safety research. Almost 20 years after the publication of the landmark IOM report, the issue’s articles examine the significant progress that has been made in the intervening years and the barriers still in place. The journal issue and the accompanying event^5^ in November 2018 brought together many of the authors; explored the emerging issues in patient safety; and discussed what gaps remain in research, policy, and implementation to reduce patient harm. The articles explore a broad range of safety initiatives, including the use of health IT to reduce medication errors and emerging efforts to improve diagnoses. The research of Drs. Ratwani and Schiff, who also participated in the event, was featured in this issue.

Stay Updated! Select here (https://www.ahrq.gov/news/newsletters/index.html) to sign up for AHRQ Health IT News and Information.

5 “Patient Safety, " Health Affairs Event, November 6, 2018. W Hotel Washington. DOI: 10.1377/he20181024.13806. available at: https://www.healthaffairs.org/do/10.1377/he20181024.13806/full/