# III PATIENT SAFETY HEALTH IT RESEARCH SPOTLIGHTS

## A AHRQ Health IT Safety Investigators Are Using Health IT to Make a Real Difference in Improving Patient Safety

Health IT includes numerous technologies that span from simple charting to advanced CDS. These technologies present increasing opportunities for improving and transforming healthcare by reducing human errors, improving clinical outcomes, and facilitating care coordination. Since the Institute of Medicine’s (IOM) landmark report in 2001, “To Err is Human,” that described using IT as a key first step in transforming and changing the healthcare environment for better and safer care, accelerated development and adoption of health IT has produced increasing amounts of evidence showing the impact on improving patient safety-related outcomes. However, some research suggests that the introduction of health IT can also potentially cause new errors and have the unintended consequences of negatively affecting patient safety. AHRQ-funded research provides critical evidence about how to identify health IT safety issues, how to remedy them, and how health IT can be safely used and implemented. The pioneering patient safety work of Drs. Raj Ratwani, Gordon Schiff, and Jason Adelman is highlighted.

Research on Health IT Safety Special Emphasis Notice (NOT-HS-16-009 (https://grants.nih.gov/grants/guide/notice-files/NOT-HS-16-009.html)): AHRQ continues to fund research on safe health IT practices related to the design, implementation, usability, and safe use of health IT by all users, including patients.

This research generates new evidence on safe health IT practices to inform policy guidance.

### Improving EHR Design Increases Patient Safety–Especially for Children

#### Poor EHR design can harm patients

Dr. Raj Ratwani and his research team identified pervasive problems with EHR systems that regularly lead to patient safety errors and other issues, regardless of vendor. “If we don’t focus on EHR technology design,” Dr. Ratwani stresses, “it will harm patients.” This issue is particularly true for pediatric patients, who are more vulnerable to EHR usability and safety challenges because of different physical characteristics and developmental issues. For example, lower body weight and less developed immune systems make children less able to tolerate even small errors in medication dosing.

Dr. Ratwani and team explored how EHR usability can adversely affect safety among pediatric patients, using data from three large academic healthcare institutions. Supported by AHRQ Health IT funding, the team developed algorithms that used NLP to recognize statistical patterns in words used in patient safety reports. This NLP algorithm can identify and code a reported safety event as related or not related to an EHR issue. They found that over a 5-year period, more than one-third of the 9,000 medication-related patient safety reports in the study were related to EHR usability issues, and nearly 20 percent of those may have harmed patients.^1^ System feedback and visual display problems were the most frequent usability issues, and they most often led to improper medication dosing, putting children at risk. In one case, the EHR did not alert a physician who ordered five times the recommended dosage of a medication for a child, which could be lethal for a child.

“Poor interface design and poor technology implementations can lead to errors that may result in patient harm, and that is unacceptable and completely fixable.”

- Dr. Raj Ratwani

#### Improving EHR design and usability will reduce errors that can lead to patient harm.

In response, Dr. Ratwani says that tools designed to assess functionality of CDS and other EHR functionality can help increase the safety of EHR systems, which will reduce errors that can lead to patient harm. Supporting more stringent policy actions is needed, such as prioritizing safety in regulating EHRs used in documenting the care of children and ensuring that data on system-related harms is collected. An end goal of his work is to establish clear guidelines for both EHR vendors and healthcare provider organizations that will lead to usability improvements and avoid harm to patients.

PRINCIPAL INVESTIGATOR | Dr. Raj Ratwani
ORGANIZATION | MedStar Health Research Institute
RESEARCH TITLE AND PROFILE LINK | Developing Evidence-Based, User-Centered Design and Implementation Guidelines to Improve Health Information Technology Usability (https://healthit.ahrq.gov/ahrq-funded-projects/developing-evidence-based-user-centered-design-and-implementation-guidelines)

### A Prototype Computerized Provider Order Entry System Reduced Medication Errors

#### Mistakes made by patients and providers can lead to medication errors.

Historically, doctors wrote prescriptions in Latin so that patients could not read the reason the medication was prescribed. It was an era of medical practice that believed keeping patients in the dark was beneficial. Medicine has come a long way in terms of patient empowerment. Today, doctors help patients to make informed choices by explaining risk and benefits of medications prescribed. However, if the patient has several prescriptions, they may confuse their medications. Medication errors may also occur during the prescribing process, including prescribing the wrong medication, wrong dose, or the wrong frequency of taking the medication.

#### Including medical indications in the prescribing process can reduce medication errors.

In medicine, an “indication” is a condition or reason for prescribing a medication or performing a test. Specifying the indication during the prescribing process can help avoid medication errors; however, the computerized prescriber order entry (CPOE) systems used by providers to prescribe medications do not usually include indications, or the process of adding it is not easy or intuitive. If the indication was recorded in the CPOE, pharmacists would have more information about the prescription, and the indication could be printed on the label of the medication bottle to help patients understand their medications.

“It is important for patients to keep their medicines straight – patients stop taking medicines without realizing which one they are taking for which condition. I recently saw a patient who stopped taking a drug she thought was for one problem (depression which was better) but was actually for her diabetes.”

- Dr. Gordon Schiff

#### Developing a prototype CPOE with indications and CDS.

Dr. Gordon Schiff and his team at the Brigham and Women’s Hospital developed and pilot tested a prototype CPOE system that incorporated indications into the prescribing process. They convened six 90-minute national webinars to gather input from providers on how to develop the prototype. Additionally, they observed providers entering medication orders to understand their process and inform the features that were ultimately included in the prototype.

The prototype gave prescribers a way to record the indication, and it showed them the drug or drugs of choice for that indication. The system included a feature that not only listed recommended medication choices, but allowed users to hover over a drug choice and read the rationale for prescribing the medication. It was also customizable such that the medication was not recommended if the patient was allergic to it.

#### The prototype CPOE outperformed two widely used CPOE systems.

Clinicians were then asked to test the prototype by entering information from eight test cases into the CPOE, and the results were compared to two leading commercial CPOE systems. Clinicians correctly placed 95 percent of orders using the prototype compared to 61 percent and 85 percent with the commercial systems. Those testing the system also reported greater satisfaction, noting it was easy to use and they would like to use it frequently. Preliminary findings from interviews with pharmacists indicated they almost universally supported including indications in the prescribing process because it would help them counsel patients, ensure medication errors were not made, and increase patients’ understanding of their medications. The prototype developed by Dr. Schiff was superior with respect to prescribing speed, safety, and user satisfaction as compared to two leading commercial CPOE systems.

Key Finding and Impact: A prototype CPOE was developed that allowed providers to record medication indications and showed them the drug of choice for that indication. Providers testing the prototype CPOE correctly placed medication orders 95 percent of the time, compared to 61 percent and 85 percent with two commercial systems.

PRINCIPAL INVESTIGATOR | Dr. Gordon Schiff
ORGANIZATION | Brigham and Women’s Hospital
RESEARCH TITLE AND PROFILE LINK | Enhancing Medication CPOE Safety and Quality by Indications-Based Prescribin (https://healthit.ahrq.gov/ahrq-funded-projects/enhancing-medication-cpoe-safety-and-quality-indications-based-prescribing)g

### Leveraging Health IT to Test Solutions That Are Replicable, Scalable, and Improve Patient Safety

#### Wrong-patient errors can affect any patient in any healthcare setting for a variety of reasons.

Dr. Jason Adelman, named as one of 50 experts leading the field of patient safety in 2018 by Becker’s Hospital Review,^2^ has led multiple AHRQ Health IT-funded research efforts centered on health IT safety. The research of Dr. Adelman, Executive Director of Patient Safety Research at Columbia University Irving Medical Center/NewYork-Presbyterian Hospital, is widespread and being replicated by other organizations. Dr. Adelman is part of the ECRI Patient Safety Collaborative, where he is advising several hospitals on how to implement the Wrong-Patient Retract-and-Reorder (RAR) Measure that he developed to evaluate the frequency of wrong-patient errors that occur through CPOE systems. When a clinician p laces an order, then cancels the order and places the same order for a different patient within the next 10 minutes, the measure flags it as a wrong-patient RAR event. While capturing the instance of retracting and reordering mistakes does not correct or prevent errors, it provides the facility with information to discover error trends along with opportunities to intercept processes that lead to such errors. Using such data as evidence of the CPOE’s potential impact on patient safety, decision makers can factor RAR measures in choosing one health IT design over another.

“Placing orders on the wrong patient should never happen. Yet, human error is very common in the healthcare environment. Healthcare is inherently complex and heavily reliant on people rather than technology to protect patients from harm. It will likely take a multi-pronged health IT approach to prevent these types of errors.”

- Dr. Jason Adelman

#### Having multipleple EHRs open simultaneously does not increase wrong-patient orders.

Dr. A delman’s AHRQ Health IT-funded research found that restricting clinicians to having one EHR record open at a time did not significantly reduce the rate of wrong-patient order errors compared with allowing up to four records to be open concurrently. His work did not support the ONC and Joint Commission recommendation that EHR systems should only allow one record to be displayed at a time. In the study, published in the May 14, 2019 issue of JAMA,^3^ using the RAR measure, Dr. Adelman and his team compared the risk of wrong-patient orders while accessing one versus four records open in a variety of clinical settings, including hospitals, EDs, and outpatient facilities. While no differences in wrong-patient orders were observed between those clinician groups, there was considerable variation in the frequency of errors in different clinical settings. The rate of wrong-patient order errors was lowest in outpatient settings, where physicians may care for one patient at a time. The highest rates, meanwhile, were seen in inpatient critical care and obstetrics units, which reflected differences in workflows and number of patients being cared for simultaneously, researchers noted. The research offers insights for healthcare systems that are trying to balance patient safety with the needs of busy clinicians who need tools for efficient workflow.

“Studies like that by Adelman and colleagues point the way to the creation of a digital learning health care system, in which the results of the interactions between clinicians (and, increasingly, patients and families) and the EHR are analyzed to help guide the strategies that lead to the highest value and most satisfying care. Having spent tens of billions of dollars digitating the health care system, it is essential to take advantage of the unique capacity of digital tools to allow clinicians and health care systems to learn from every click.” -editorial by Drs. Wachter, Murray, and Adler-Milstein^4^

#### The right patient, right dose, right medication, right route, and right frequency.

The Health IT Program has also funded Dr. Adelman to extend research on RAR, to validate and evaluate the reliability of RAR using a different EHR system, so it can be implemented and may advance interventions to prevent these serious and complicated safety issues. The intent is to develop health IT measures that identify deviations from the Five Rights of Medication Safety: right patient, right dose, right medication, right route, and right frequency.

#### Use of photographs to prevent errors.

An additional Adelman-led, AHRQ-funded study is assessing the effectiveness of using patient photographs as an additional identifier in the EHR system to avoid wrong-patient errors when using CPOE systems. The research team will conduct a randomized controlled trial of wrong-patient error rates between systems with patient photos and without. Ultimately, the team plans to develop a toolkit with guidance to help other health systems in implementing patient photos in EHR systems.

PRINCIPAL INVESTIGATOR | Dr. Jason Adelman
ORGANIZATION | Columbia University and New York Presbyterian Hospital
RESEARCH TITLES AND PROFILE LINKS | Assess Risk of Wrong Patient Errors in an EMR That Allows Multiple Records Open (https://healthit.ahrq.gov/ahrq-funded-projects/assess-risk-wrong-patient-errors-emr-allows-multiple-records-open); Develop and Validate Health IT Safety Measures To Capture Violations of the Five Rights of Medication Safety (https://healthit.ahrq.gov/ahrq-funded-projects/develop-and-validate-health-it-safety-measures-capture-violations-five-rights); Providing Evidence and Developing a Toolkit to Accelerate the Adoption of Patient Photographs in Electronic Health Records (https://healthit.ahrq.gov/ahrq-funded-projects/providing-evidence-and-developing-toolkit-accelerate-adoption-patient)

The impact of these AHRQ-funded studies will extend beyond the original research settings. Their work can be widely disseminated as vendors and healthcare organizations and systems can use their findings as they design and implement health IT to improve patient safety as well as to inform decision making at the policy level.

1 https://www.ncbi.nlm.nih.gov/pubmed/30395517

2 https://www.beckershospitalreview.com/lists/50-experts-leading-the-field-of-patient-safety-2018.html

3 https://jamanetwork.com/journals/jama/fullarticle/2733207

4 https://jamanetwork.com/journals/jama/article-abstract/2733189