# II 2018 RESEARCH SUMMARY

## A Overview

AHRQ’s Health Information Technology (IT) Program’s mission is directly aligned with the overall AHRQ mission. Through rigorous research, AHRQ generates the ground-breaking knowledge, tools, and data needed to improve health system performance and health outcomes. The research products yielded may be used by patients, healthcare professionals, and policymakers to make informed decisions based on the most current evidence available. Furthermore, AHRQ’s cutting-edge research galvanizes collaboration across agencies within the U.S. Department of Health and Human Services and with other partners to empower evidence-based decision making at all levels of the healthcare system and to achieve the goals of high-quality care, cost-effective spending of healthcare dollars, and improved health for the American people.

### In 2018, the AHRQ Health IT Program supported:

- 141 research grants and four research contracts
- awarded to over 75 distinct institutions
- in 31 States and the District of Columbia.

Created with mapchart.net@

Map of the United States showing the number of projects supported by the AHRQ Heath IT Program in 2018: 0 projects (19 states): AR, DE, ID, FL, HI, KS, LA, ME, MS, MT ND, NJ, NV, OK, RI, SD, VT, WV, WY 1-2 projects (13 states, DC): AL, AK, DC, GA, IA, KY, MN, NE, NH, NM, OR, TN, TX, UT 3-4 projects (8 states): AZ, CO, CT, MO, OH, PA, SC, VA 5-10 projects (6 states): IL, IN, MI, NC, WA. WI 11+ projects (4 states): CA, MA, MD, NY

### In 2018, the AHRQ Health IT Program continued to fund research in response to 18 past and present funding opportunities.

The AHRQ Health IT funding opportunities are designed to fund health IT research that fill gaps in the knowledge and understanding of the field, which will lead to improved design of health IT systems. The program accomplishes this through a variety of grant and contract mechanisms that support different types of health services research projects, including:

- Exploratory and developmental research grants that support research in the early and conceptual stages of development.
- Pilot and feasibility studies.
- Randomized controlled trials and other studies of technology effectiveness.
- Secondary analysis of existing data.
- Dissemination work that scales evidence-based research more broadly.

In addition, AHRQ supports the next generation of heath IT researchers by funding promising new investigators through awards intended to foster their career development in health services IT research.

### In 2018, AHRQ-funded health IT researchers:

- Published over 100 research articles in peer-reviewed journals and book chapters.
- Presented their research at a variety of health IT, medical, and other key conferences.

## B Key Research Findings

Health IT can be a powerful enabler for patients, clinicians, and health systems working to positively affect the quality and safety of healthcare. The AHRQ Health IT Program funds research to create actionable findings around “what and how health IT works best” for these healthcare stakeholders. The following summary presents impactful health IT-funded research for each of these three focus areas.

### AHRQ-Funded Research Improves Care of Patients and Their Engagement in Care

AHRQ Health IT-funded research supports patient-centered care, which includes the use of patient-reported outcomes (PROs). Also, while technology usability is a cross-cutting theme throughout most of AHRQ’s health IT-funded research, 2018 findings underscored the need to recognize the unique usability requirements of priority patient populations. The following research exemplifies AHRQ’s recently completed patient-focused research. Select the hyperlink on the PI’s name for more information on the research.

Patient-Centered Care (PCC) is a respectful and responsive approach to fulfilling patients’ healthcare preferences, needs, and values. AHRQ supports the importance of PCC through research that uses health IT to engage patients and their caregivers, and empowers them with knowledge to make more informed decisions about their care. The following research highlights key achievements in the area of PCC:

- Dr. David Vawdrey (https://healthit.ahrq.gov/ahrq-funded-projects/addressing-hospital-patient-information-needs-using-personal-health-record) provided inpatients with access to a patient portal and found that it increased patient engagement with health information during hospitalizations for cardiac conditions.
- A patient-centered clinical decision support (CDS) app for management of minor head injuries was developed by Dr. Edward Melnick (https://healthit.ahrq.gov/ahrq-funded-projects/clinical-decision-support-mild-traumatic-brain-injury) based on usability feedback from patients and providers. Giving clinicians the tools to support patient-provider communication resulted in fewer computed tomography (CT) scans ordered, higher physician trust by patients, and great er patient knowledge. Read the impact story here!
- Dr. Eneida Mendonca (https://healthit.ahrq.gov/ahrq-funded-projects/virtualized-homes-tools-better-discharge-planning) conducted a proof-of-concept study that linked scanned models of the interior of patients’ homes to the electronic health record (EHR) to ultimately support care teams in tailoring the discharge plan to the patient’s home environment. Physicians participating in focus groups reacted positively to the tool and reported its potential utility to support planning and preparing patients for discharge, especially for patients with complex discharges, greater illness burden, and those requiring rehabilitation.
- Dr. Jessica Ancker (https://healthit.ahrq.gov/ahrq-funded-projects/improving-healthcare-quality-user-centric-patient-portals) engaged patients in managing their health and care through a patient-centric portal designed to match patients’ needs. The research indicated that patients consider it too much work to track their health data and often lack a clear understanding of tasks required to manage their personal health information.

Patient-Reported Outcomes (PROs) are a component of PCC that use health information provided by the patient via technologies such as mobile apps or wearable devices to monitor disease symptoms and provide individualized care and treatment. Notable AHRQ-funded research integrated PROs into the care and management of various health conditions. Several examples are provided below:

- Dr. Robert Rudin (https://healthit.ahrq.gov/ahrq-funded-projects/using-mhealth-and-patient-reported-outcomes-deliver-evidence-based-asthma-care) developed and tested the feasibility of an app that allows patients to report and share their asthma symptoms with providers by answering five simple questions to inform clinical care. Patients reported the app was simple and easy to use, increased awareness of their asthma symptoms and flares, made them feel more connected to their providers, and avoided emergency care. Through a second grant (https://healthit.ahrq.gov/ahrq-funded-projects/integrating-patient-reported-outcomes-routine-primary-care-monitoring-asthma) from AHRQ, Dr. Rudin is enhancing the app and evaluating whether it facilitates enhanced asthma self-management and patient-provider communication in the primary care setting. Read the impact story here!
- Dr. Rebecca Schnall’s (https://healthit.ahrq.gov/ahrq-funded-projects/use-mhealth-technology-supporting-symptom-management-underserved-persons-living) “mVIP” mobile health app provided real-time symptom management strategies to people with HIV. Patients reported their symptoms in the mVIP, and the app provided customized self-care strategies based on their symptoms. The app helped patients reduce symptoms of anxiety, depression, neuropathy, fever, chills, sweating, and weight loss or wasting. Read the impact story here!
- Dr. Bengisu Tulu (https://healthit.ahrq.gov/ahrq-funded-projects/tjr-guru-mobile-app-shared-informed-decisionmaking-total-joint-replacement) developed an app for tracking pain and activity levels among patients with osteoarthritis. Patients reported use of the app led to more data-driven conversations with their doctors and increased their active participation in the decision-making process.

Priority Populations, or groups at risk for experiencing health disparities, may have unique health IT usability requirements. Since usability is key to ensuring that health technology meets the needs of the individuals who use it, AHRQ funded the following four researchers to examine the ease and learnability of technology for priority populations.

- Dr. Donna Kazemi (https://healthit.ahrq.gov/ahrq-funded-projects/mhealth-delivery-motivational-intervention-address-heavy-drinking-among-college) designed an app to address risky alcohol use among college students. The research indicated the app had good usability, was effective, and was more cost effective than in-person interventions. Read the impact story here!
- To support healthy food decisions, Dr. May May Leung’s (https://healthit.ahrq.gov/ahrq-funded-projects/intervention-inc-interactive-nutrition-comics-urban-minority-youth) interactive nutrition comic for dietary self-management increased positive beliefs and attitudes toward fruits, vegetables, and water among minority youth. Children ate more vegetables and drank more water, as well as decreased their sugar intake, from the beginning of the study to the end of the study. Read the impact story here!
- Dr. Rupa Valdez’s (https://healthit.ahrq.gov/ahrq-funded-projects/accessibility-and-beyond-designing-consumer-health-it-disabled-individuals) research concluded that patient-facing technology must be redesigned or enhanced to better allow individuals with disabilities to fully engage with technology and demonstrated the importance of partnering with individuals with disabilities to optimize technology design for their use. Read the impact story here!
- With extensive and iterative user feedback, Dr. Mark Andrew Connelly (https://healthit.ahrq.gov/ahrq-funded-projects/minimizing-stress-maximizing-success-physicians-use-health-information) developed an app for youth with juvenile idiopathic arthritis that provided tailored information for the patient on effective pain management strategies.

### Supporting Clinicians' Work

Research funded by AHRQ aims to support clinicians and other healthcare professionals in providing health services. The projects highlighted below share the goal of improving the experience of health professionals who use health IT. The featured researchers investigated how health professionals interact with technology and how technology can be optimally integrated in tasks undertaken on a daily basis. Select the hyperlink on the PI’s name for more information on the research.

Human Factors Design is the study of human behavior, the environment, and technology with the goals of reducing human error and increasing productivity. In the context of health IT, human factors design focuses on healthcare professionals’ abilities and limitations when interacting with computers or other technologies such as EHRs. Given the increasing role and complexity of technology in healthcare, AHRQ funded the following researchers to study the impact of technology on clinicians, and to test strategies to improve clinicians’ experiences using technology in the healthcare setting.

- Through focus groups and a survey of providers, Dr. Philip Kroth (https://healthit.ahrq.gov/ahrq-funded-projects/minimizing-stress-maximizing-success-physicians-use-health-information) found that use of health information communication technology (HICT) contributes to work-related stress, burnout, and lack of job satisfaction. The challenges of HICT include excessive data entry, lack of work-life balance, and poor posture and physical pain from using HICT. Good self-care, exercise, and resiliency training were found to be helpful coping strategies. Dr. Kroth recommended efforts to reduce information overload and changing policy so that notes focus on documenting clinical care, rather than supporting billing.
- Dr. Jason Saleem (https://healthit.ahrq.gov/ahrq-funded-projects/ambulatory-clinic-exam-room-design-respect-computing-devices-enhance-patient) tested a redesigned clinic exam room that included a mobile computer station and wall-mounted monitor for ease of repositioning. This room configuration led to more time sharing the screen with patients, reduced workload, and gave clinicians greater situational awareness. Read the impact story here!
- Dr. Foster Goss (https://healthit.ahrq.gov/ahrq-funded-projects/natural-language-processing-identify-and-rank-clinically-relevant-information) developed a natural language processing (NLP) EHR search tool that automatically identifies and ranks relevant clinical information based on a patient’s presenting complaint within the emergency department (ED) setting.
- To support clinician productivity, Dr. Genevieve Melton-Meaux (https://healthit.ahrq.gov/ahrq-funded-projects/discovery-and-visualization-new-information-clinical-reports-electronic-health), employed NLP to identify and visually distinguish new versus redundant information in clinical notes. Findings will be used to inform future EHR design considerations to improve usability and decrease clinician cognitive burden.

Clinical Work Flow is a defined series of steps taken by a clinician to provide care or treatment to a patient. With deliberate and structured planning, testing, and implementation processes, health IT can support clinical workflow and enhance clinicians’ efficiency. The following two AHRQ-funded researchers investigated the impact of health IT on clinical workflow.

- Dr. Hardeep Singh (https://healthit.ahrq.gov/ahrq-funded-projects/decision-making-and-clinical-work-test-result-followup-health-information) studied how clinicians complete tasks related to laboratory test results to understand the reasons for delayed diagnoses resulting from failure to follow up on test results. Dr. Singh found that common barriers include poorly designed communication interfaces between the EHR and diagnostic services and usability challenges with the EHR. He recommended using dedicated personnel to follow up on lab results and implementing EHR designs to facilitate followup of laboratory test results.
- Dr. Scott Ryan Levin (https://healthit.ahrq.gov/ahrq-funded-projects/hopscore-electronic-outcomes-based-emergency-triage-system) tested E-triage, a machine-learning algorithm, to predict the risk of adverse outcomes in the ED. E-triage improved identification of low-risk patients, allowing providers to focus their time and attention on patients with greater risk. Additionally, the algorithm reduced the time to decide whether to admit a patient by 58 minutes and the time to see a clinician by 10 minutes.

### Improving the Delivery of Health Services at the Health Systems Level

AHRQ-funded research aims to improve the delivery of health services at the health systems or organizational level. Efforts to share health information across different technologies and healthcare environments, and leveraging data and technologies to strengthen the quality of services delivered were key aspects of research projects focused on health systems. Select the hyperlink on the PI’s name for more information on the research.

Interoperability allows information to flow from one information system to another with the goal of improving health outcomes, quality of care, safety, cost-effectiveness, and access to health services. AHRQ funded the following research to develop interoperable systems in support of population health.

- Dr. Brian Dixon (https://healthit.ahrq.gov/ahrq-funded-projects/improving-population-health-through-enhanced-targeted-regional-decision-support) leveraged a health information exchange (HIE) to improve public health reporting in primary care settings. A decision support intervention delivered pre-populated case reporting forms through the HIE when laboratory results for reportable diseases were positive. As a result, reporting rates and completeness of the forms significantly improved, and feedback from providers and public health professionals was positive.
- Dr. Jason Shapiro (https://healthit.ahrq.gov/ahrq-funded-projects/advancing-quality-measurement-and-care-improvement-health-information-exchange) used real-time data from an HIE to validate quality measures of potentially avoidable visits to the ED. Compared to data from EHRs, data from the HIE increased the identification of early return visits and frequent ED users, thereby improving the accuracy of the quality measures. Future application of this work has the potential to reduce data fragmentation by increasing providers’ access to information across the health system.
- With funding from AHRQ, the MITRE Corporation launched CDS Connect (https://healthit.ahrq.gov/health-it-tools-and-resources/clinical-decision-support-cds) to facilitate translation of evidence-based care into clinical practice with interoperable CDS. CDS Connect includes an online repository of CDS artifacts—various types of evidence-based medical knowledge, such as clinical guidelines that may be used to create prototypes for sharing CDS across health settings and technologies. This work provides the framework for improving healthcare outcomes via CDS creation, discovery, integration, and implementation using evidence-based interoperable CDS artifacts. The repository of CDS artifacts is available here (https://cds.ahrq.gov/cdsconnect/artifact_discovery) on the AHRQ website.
- Dr. Kathleen Cartmell (https://healthit.ahrq.gov/ahrq-funded-projects/reducing-hospital-readmission-rates-implementing-inpatient-tobacco-cessation) tested an interactive voice recognition (IVR) tobacco dependence treatment service for inpatients that linked an EHR, tobacco cessation program, and statewide healthcare utilization data. At 30 days after discharge, smokers using the IVR service were significantly less likely to be readmitted compared to those who did not use the service. Their healthcare charges were also, on average, $7,299 lower. Read the impact story here!

Quality Improvement, often implemented iteratively, is the process of attaining a higher level of performance or quality compared to previous levels. In the healthcare environment, quality improvement efforts may focus on strengthening health services delivery to serve the ultimate goal of improving patients’ health and experiences with the health system. The following two AHRQ-funded research projects, both conducted in pediatrics, used data in the EHR with the shared goal of improving quality. Select the hyperlink on the PI’s name for more information on the research.

- Dr. Elizabeth Alpern (https://healthit.ahrq.gov/ahrq-funded-projects/improving-quality-pediatric-emergency-care-using-electronic-medical-record) developed an emergency care data registry for pediatric patients using EHRs. The registry contains data from more than two million ED visits representing more than 900,000 patients. Data from the registry have been used for quality improvement audits and feedback, as well as health services research.
- Dr. Naomi Bardach (https://healthit.ahrq.gov/ahrq-funded-projects/novel-it-create-patient-integrated-quality-improvement) created and pilot tested FIQS, the Family Input to Quality and Safety tool, which allows pediatric patients and their caregivers to provide safety reports regarding their inpatient care. Participants had a positive experience using the tool. Additionally, they endorsed its continued use, thereby demonstrating the feasibility of collecting real-time safety reports from patient and family members so that health systems can readily take action based on these data.

## C Impact Stories from AHRQ-Funded Work

AHRQ-funded research generates findings that aim to make a tangible difference in patients’ health and engagement in their care, clinicians’ experience and effectiveness in providing care and treatment, and the overall effectiveness and quality of the services delivered through the health system. The following impact stories further amplify and demonstrate the effect of AHRQ-funded research mentioned above.

### Decreasing Tobacco-Related Healthcare Costs Using Interactive Voice Response Technology

#### Tobacco use and its related morbidity and mortality are burdens to the U.S. health system.

Tobacco use in the United States continues to be a significant healthcare concern. In addition to causing approximately 480,000 deaths annually and resulting in nearly $300 billion in healthcare spending each year, tobacco use is also a known risk factor for hospital admissions and readmissions. The benefits of in-hospital smoking cessation programs have been documented; however, these programs can be expensive to implement. Dr. Kathleen Cartmell and her research team at the Medical University of South Carolina (MUSC) wanted to examine the cost-effectiveness of these programs and their impact on hospital readmission rates.

#### Using technology to follow up with in-hospital tobacco treatment services.

Implemented in 2014 to meet Joint Commission tobacco treatment standards, MUSC’s automated opt-out Tobacco Dependence Treatment Service (TDTS) interfaced with the hospital’s admission and discharge records to identify tobacco users and refer these patients to in-hospital tobacco cessation services. Using Interactive Voice Response (IVR), patients received automated followup phone calls to assess tobacco use and provide referrals to community tobacco cessation services at 3, 14, 30, 90, and 180 days after hospital discharge.

#### Smoking cessation using IVR can reduce readmission rates and lower healthcare charges.

Dr. Cartmell examined differences in readmission rates and healthcare costs between TDTS users and those who did not receive the service. Those using the TDTS service were 23 percent less likely to be readmitted to the hospital 30 days after discharge. Their healthcare charges were also, on average, $7,299 lower than smokers who did not receive TDTS. These findings suggest that an automated, opt-out inpatient TDTS service could decrease readmissions and healthcare costs for patients, increase efficiency in patient care for the hospital, and decrease claims for insurers. Dr. Cartmell wants to see additional studies to validate the findings, whose results may encourage healthcare systems to invest in TDTS programs.

“If we can show providing a tobacco cessation program is truly a driver of healthcare utilization and costs, that becomes a tremendous incentive for hospital systems to provide these kind of programs.”

– Dr. Kathleen Cartmell

Key Finding and Impact: Automated, opt-out inpatient tobacco cessation services delivered by interactive voice response decreases readmissions and healthcare charges.

PRINCIPAL INVESTIGATOR | Kathleen Cartmell, Ph.D.
ORGANIZATION | Medical University of South Carolina
RESEARCH TITLE AND PROFILE LINK | Reducing Hospital Readmission Rates by Implementing an Inpatient Tobacco Cessation Service Driven by Interactive Voice Recognition Technology (https://healthit.ahrq.gov/ahrq-funded-projects/reducing-hospital-readmission-rates-implementing-inpatient-tobacco-cessation)

### Reducing Risky College Drinking Through The Use of Cutting Edge mHealth Technology

#### Heavy alcohol use and its related consequences are major health problems for U.S. universities.

High-risk drinking in college students has dangerous and numerous consequences. Addressing alcohol use in college students has often relied on in-person interventions, which are expensive, difficult to sustain, and often inaccessible. Recognizing the almost universal use of smartphones (SP) and “apps” (applications) in this young adult population, researchers at the University of North Carolina at Charlotte hoped to reduce high-risk drinking through the use of a proven, evidence-based alcohol intervention using mHealth technology.

In addition to ac ademic failure, the c onsequences of alcohol abuse can include blackouts, violence, suicide, H IV-related sexual risk-taking, and sexual assault.

#### Using an adapted Brief Motivational Interviewing Smartphone App (BMI+SP) as a real-time alcohol intervention.

Dr. Kazemi and her national interdisciplinary team of researchers, including experts in psychology, computer science, mathematics, and nursing, aimed to address the cost and accessibility challenges of in-person alcohol interventions by developing BMI+SP, a smartphone app that uses an adapted Brief Motivational Interviewing (BMI) intervention to encourage users to change their high-risk drinking behaviors. BMI+SP has multiple interactive components designed to engage the user and provide customized messaging based on user characteristics. Dr. Kazemi and team found a significant reduction in alcohol use and alcohol-related consequences in students who used the app for 6 weeks compared to students who did not use the app.

#### mHealth apps can reach youth to reduce alcohol use and intervention costs.

This study suggested that mHealth apps can help to address dangerous alcohol use in young adults. BMI+SP and similar apps have the potential to reduce alcohol intervention costs, reach more individuals than traditional in-person interventions, and be adapted for use across other areas of health concerns. Dr. Kazemi reports that these findings will inform future, more extensive studies looking at the usability, sustainability, efficacy, and cost-effectiveness of mHealth interventions to address hazardous drinking among young adults. This innovative approach also has the potential to be translated to address other important health issues in vulnerable populations.

Key Finding and Impact: Apps to address dangerous alcohol use in college age adults may be as effective, and more cost-effective, as traditional in-person interventions.

PRINCIPAL INVESTIGATOR | Donna Kazemi, PhD
ORGANIZATION | University of North Carolina at Charlotte
RESEARCH TITLE AND PROFILE LINK | mHealth Delivery of a Motivational Intervention to Address Heavy Drinking Among College Freshman (https://healthit.ahrq.gov/ahrq-funded-projects/mhealth-delivery-motivational-intervention-address-heavy-drinking-among-college)

### Reducing Childhood Obesity Risk Using an Interactive Digital Comic Book

#### Childhood obesity is a serious public health issue.

Childhood obesity has significant short- and long-term health consequences. Obese children have higher rates of cardiovascular disease and diabetes in childhood, as well as an increase in morbidity and mortality in adulthood. Often associated with the consumption of sugary beverages and energy dense or low fiber foods, childhood obesity rates in the United States are highest in low-income and minority children. Dr. May May Leung wanted to address this issue using an original and culturally relevant digital health platform.

Children live in a media-saturated environment. Innovative interventions are needed to engage children and interest them in health-promoting behaviors.

#### Designing comic books to reach urban minority youth.

In this pilot study, Dr. Leung’s multidisciplinary research team at Hunter College-City University of New York developed Intervention INC, an interactive web-based comic that addresses behaviors associated with obesity in children aged 9–12 years. By using the individual, social, and environmental factors that affect the dietary choices of urban minority youth and the feeding practices of their parents, Dr. Leung tailored the six-chapter comic to reflect the unique cultural characteristics of the study population. Recognizing that sedentary behaviors such as using computers, tablets, and smartphones also contribute to childhood obesity rates, Dr. Leung exposed participants to a single chapter of the comic each week and designed each chapter to be read in 15–20 minutes.

#### Increases in healthy eating behaviors among participants.

The research team found that Intervention INC was highly acceptable among children and their parents, but more importantly, preliminary results show that participants who read the comic demonstrated significantly greater improvements in vegetable, water, and sugar intake; improved attitudes toward vegetable consumption; and showed greater self-efficacy toward fruits, vegetables, and water. Dr. Leung would like to see additional large-scale studies for the comic in real-world settings and adaptation of the tool to other ethnic groups.

Key Finding and Impact: Children who read the comic ate more vegetables and drank more water, as well as decreased their sugar intake, from the beginning of the study to the end of the study.

PRINCIPAL INVESTIGATOR | May May Leung, PhD, RDN
ORGANIZATION | Hunter College, The City University of New York
RESEARCH TITLE AND PROFILE LINK | Intervention INC: Interactive Nutrition Comics for Urban Minority Youth (https://healthit.ahrq.gov/ahrq-funded-projects/intervention-inc-interactive-nutrition-comics-urban-minority-youth)

### When Costly and Potentially Harmful CT Scans Are Not Necessary

#### Is that CT scan in the patienťs best interest?

While the increased use of diagnostic imaging tests like CT has outpaced healthcare growth, the use of these tests does not always reflect patient-centered care. Frequently overused in the ED setting, CT scans are often ordered in scenarios where there is no evidence of improved patient outcomes. Additionally, non-essential CT scans can result in increased healthcare costs, exposure to unnecessary radiation, and longer hospital stays.

“About 1 out of every 3 CT scans that are performed in the ER for minor head injury are not clinically indicated.”

- Dr. Edward Melnick

#### Aligning best practices for CT scans for patients with minor head injuries.

Dr. Edward Melnick and his research team at Yale University sought to identify the non-clinical, human factors that promote or inhibit the appropriate use of CT in patients presenting to the ED with minor head injury. They talked to patients and providers to inform the development of the Concussion or Brain Bleed application (integrated patient- and provider-facing app), an innovative CDS tool that integrated a patient-centered decision aid and CDS at the bedside for the management of minor head injury in the ED. The app was based on the Canadian Computed Tomography Head Rule (CCTHR), a clinical decision rule designed and validated to safely reduce imaging in minor head injury.

#### Sorry, Doctor, did you say I donť need a CT?

The team’s overall goal was to better prepare clinicians to guide patients with minor head injuries on appropriate CT use and to evaluate the tool through a pilot study. When physicians expressed empathy and had increased knowledge of when CT use was appropriate, patients accepted the recommended treatment, even when not utilizing advanced imaging like CT scan. While development of CDS for minor head injuries increased the likelihood of clinically appropriate CT, implicit in this process is the time spent with the patient to assure they understand and are comfortable with a treatment plan that does not involve CT.

Key Finding and Impact: Giving clinicians the tools to support patient-provider communication could result in fewer CTs ordered, higher physician trust, and higher patient knowledge in cases involving minor head injuries.

PRINCIPAL INVESTIGATOR | Edward Melnick, MD, MHS
ORGANIZATION | Yale University
RESEARCH TITLE AND PROFILE LINK | Clinical Decision Support for Mild Traumatic Brain Injury (https://healthit.ahrq.gov/ahrq-funded-projects/clinical-decision-support-mild-traumatic-brain-injury)

### A Simple Mobile Application is Key to Patient Engagement in Reporting and Monitoring of Asthma Symptoms

Seeing value in using PROs data for research purposes, Dr. Robert S. Rudin from the RAND Corporation recognized that PROs data could also be used to improve patient care. People with asthma have better outcomes and fewer flareups when their symptoms are routinely monitored and managed by clinicians. Using mobile applications to report asthma symptoms to clinicians would allow for more timely management of asthma systems.

Dr. Rudin and his research team designed a patient-facing mobile phone app for people with asthma using user-centered design principles and an iterative process that engaged patients and providers. Patients received a weekly prompt to answer five standardized questions about their current asthma symptoms. A care manager, such as a nurse or medical assistant, received notifications if patient-reported symptoms met specific conditions of worsening severity.

#### User feedback is important to the development of mobile health apps.

Keeping patients engaged is often a challenge in healthcare; therefore, the research team knew they had to develop an app that would be of value to patients so that they would continue to use it. Dr. Rudin commented, “Using a user-centered design process, the patients reveal to you what they want for the design. I’ve yet to have an interaction with a user where I didn’t learn something.” The user-centered design process informed the development of the app and the practice model for the intervention. For instance, physicians invited their patients to use the mobile app, because the researchers found during the formative research that patients are more likely to adhere to recommendations made by their physicians.

#### A simple solution to engage patients.

Dr. Rudin and his team conducted a 6-month feasibility study in two subspecialty care clinics, analyzing app usage logs and data from interviews conducted with patients and clinical staff. At the end of 6 months, they were surprised and pleased to find high patient engagement: 92 percent of patients were still completing weekly PRO questionnaires. Over 80 percent of patients received at least one call based on their weekly PRO responses. Patients reported that the app was simple and easy to use, increased awareness of their asthma symptoms and flares, made them feel more connected to their provider, and avoided emergency care. Providers reported minimal workflow burden.

The importance of keeping it simple “Too often we try to load up interventions with bells and whistles, and then you don’t know exactly why it works or doesnť work. For this intervention, we discovered that asking patients five simple questions once a week, with the option to call the provider, kept patients engaged in asthma management and made them feel more connected with their physicians.”

- Dr. Robert S. Rudin

#### Scale and spread of this successful application and model.

Dr. Rudin has been funded for future work by AHRQ to scale and spread this successful app and practice model. For this current research, Dr. Rudin and his team are applying user-centered design processes to enhance and adapt the app in a primary care setting, where much of asthma disease management occurs. The enhancements will include recording peak flows and details on recent symptoms and triggers, which were suggested by patients and providers during the original research project. The enhanced app and model will be rigorously evaluated with a randomized controlled trial to understand the impact of the app on quality of life and asthma-related healthcare utilization.

Key Finding and Impact: A simple app, designed with input from patients, resulted in 92 percent of patients continuing to report their asthma outcomes at the end of the study. A tool like this simple app may help patients better control their asthma and prevent emergency care.

PRINCIPAL INVESTIGATOR | Robert S. Rudin, PhD
ORGANIZATION | RAND Corporation
RESEARCH TITLES AND PROFILE LINKS | Integrating Patient-Reported Outcomes into Routine Primary Care: Monitoring Asthma Between Visits (https://healthit.ahrq.gov/ahrq-funded-projects/integrating-patient-reported-outcomes-routine-primary-care-monitoring-asthma); Using mHealth and Patient-Reported Outcomes to Deliver Evidence-Based Asthma Care (https://healthit.ahrq.gov/ahrq-funded-projects/using-mhealth-and-patient-reported-outcomes-deliver-evidence-based-asthma-care)

### Using Technology to Enhance Patient Communication During Clinic Visits

#### Computers have advantages, but may interfere with patient communication.

Computer use by providers during clinical visits enhances how patient data are documented and organized; however, it may have a negative impact on the patient-provider relationship. For instance, providers documenting information in the electronic medical record during a visit may maintain less eye contact with the patient. Dr. Jason Saleem at the University of Louisville studied the impact of exam room layout on patient-centered care, with the goal of using technology as a mediating device between the patient and provider.

#### Assessing the impact of a redesigned clinic exam room on patient-provider communication.

In collaboration with the Veterans Health Administration, Dr. Saleem tested a prototype design to better incorporate computers in the clinic exam room. New wall-mounted systems allowed providers to share the computer monitor with patients while easily orienting themselves toward the patient and keeping the computer screen in view. A new mobile computer workstation allowed providers to rearrange the clinic room, including simply pushing the computer away when not useful or needed.

“Primary care providers are incredibly overburdened: every second counts. We can find ways to improve their experience and use technology to improve their interactions with patients.”

- Dr. Jason Saleem

#### Using technology to enhance and not disrupt communication.

The standard room design and the prototype were compared through a lab simulation study. Although providers were heavily focused on the patient in both study scenarios, providers using the standard room design had less situational awareness and greater cognitive workload because they needed to more frequently change their orientation between the computer and the patient. Field observations conducted by Dr. Saleem found that both providers and patients were enthusiastic about the flexibility to move and share the computer screen. In addition to increasing patient-centeredness, this study indicated the feasibility of aligning patient technology with the model of patient care.

Key Finding and Impact: Leveraging clinic room configuration allows the computer to become a facilitator to the patient visit, rather than a barrier between the provider and patient.

PRINCIPAL INVESTIGATOR | Jason J. Saleem, Ph.D.
ORGANIZATION | University of Louisville
RESEARCH TITLE AND PROFILE LINK | Ambulatory Clinic Exam Room Design With Respect to Computing Devices to Enhance Patient Centeredness (https://healthit.ahrq.gov/ahrq-funded-projects/ambulatory-clinic-exam-room-design-respect-computing-devices-enhance-patient)

### Using Mobile Technology to Self-Manage HIV Symptoms

#### HIV has evolved from an acute illness to a chronic disease that requires chronic disease management.

People with HIV are living longer due to the availability of improved treatments, including medication regimes that may have symptoms and side effects. Managing these symptoms is crucial for maintaining quality of life; however, overburdened providers often have limited time to optimally manage symptoms. Racial and ethnic minorities, as well as those of low socioeconomic status, often have less access to health information and consequently experience symptoms at higher rates than other people with HIV.

#### Developing a health IT tool that is useful and helpful to underserved populations.

Recognizing the importance of symptom management in at-risk populations, Dr. Rebecca Schnall and her Columbia University-based research team developed an mHealth app, called the mobile Video Information Provider (mVIP), with evidence-based self-care strategies that guide people with HIV in self-managing their HIV-related symptoms. Tested using a rigorous user-centered design process, Dr. Schnall’s randomized pilot study is one of the first to examine mobile app use within a population of individuals of low income and largely racial and ethnic minorities.

“This is an opportunity to be able to disseminate this health information to communities that are the most at risk for not being able to access their health information, are least likely to self manage their health, and have the poorest health outcomes.”

- Dr. Rebecca Schnall

#### mVIP users reported a decrease in HIV-related symptoms.

mVIP use was associated with an improvement in symptoms, high user satisfaction, and a self-reported increase in medication adherence. Persons who had access to mVIP’s care strategies reported less anxiety, depression, fevers, neuropathy, and weight loss than persons who did not have access to the care strategies. Technologies such as mVIP could result in increased quality of life, reduced administrative burden, and reduced health care costs due to decreased visit complexity and overall fewer visits. While Dr. Schnall recommends a larger and longer study be conducted of this app, she believes the current findings could guide future work in the application of the app to other chronic care diseases.

Key Finding and Impact: mHealth technologies can decrease HIV-related symptoms in medically underserved populations.

PRINCIPAL INVESTIGATOR | Rebecca Schnall, RN, PhD
ORGANIZATION | Columbia University Health Sciences
RESEARCH TITLE AND PROFILE LINK | Use of mHealth Technology for Supporting Symptom Management in Underserved Persons Living with HIV (https://healthit.ahrq.gov/ahrq-funded-projects/use-mhealth-technology-supporting-symptom-management-underserved-persons-living)

### Understanding and Designing Health IT for Persons With Disabilities

As individuals become more involved in the self-management of their healthcare needs, consumer health IT is increasingly tied to patient outcomes and engagement. It is well documented that people with disabilities face inequities when accessing healthcare, including consumer health IT. Little has been done, however, to address these disparities. To capture the needs of all patient populations, health IT design must be inclusive of individuals who face barriers to accessing healthcare, including those with physical, cognitive, and sensory disabilities.

#### Identifying the unique needs for disabled individuals.

Dr. Rupa Valdez and her University of Virginia-based research team aimed to improve access to health IT for individuals with disabilities. Dr. Valdez studied how this population communicated health information within their social networks and the challenges they encountered when accessing health IT. Individuals discussed necessary supports, conversations about how much information to disclose and to whom, statements about one’s disability and their rights as a person with a disability, and how their disability impacted their health communication and decision making. Using this information, she was then able to identify which communication characteristics and health IT features needed to be evaluated to guide the design of health IT responsive to the needs of individuals with disabilities. Dr. Valdez emphasizes that the needs of this population must be considered early and often in the design process; health IT developers should view individuals with disabilities as partners in health IT design and not make assumptions about the experiences, needs, and preferences of their customers.

“Research has shown that the impact of someone’s disability is changeable…and can be addressed, in part, through design.”

- Dr. Rupa Valdez

#### Encouraging patient-centered health IT.

Dr. Valdez recommends that providers and healthcare administrators consider the patient’s limitations when selecting or implementing technology. Her research suggests that the role of patients and the general public, as advocates for change, will be crucial in encouraging health equity and enforcing disability rights in the future.

Key Finding and Impact: Health information communication for individuals with disabilities is multidimensional and includes conversations about support, disclosure, advocacy, and logistics. Informed changes to content, functionality, interfaces, and technology platforms increases health IT usability and usefulness for individuals with disabilities.

PRINCIPAL INVESTIGATOR | Rupa Valdez, Ph.D.
ORGANIZATION | University of Virginia
RESEARCH TITLE AND PROFILE LINK | Accessibility and Beyond: Designing Consumer Health IT for Disabled Individuals (https://healthit.ahrq.gov/ahrq-funded-projects/accessibility-and-beyond-designing-consumer-health-it-disabled-individuals)

## D AHRQ's Emerging and Innovative Newly Funded Research in 2018

The Health IT Program at AHRQ continues to fund foundational research to identify solutions to ensure that health IT is designed and implemented in ways that improve quality and safety without placing excessive burden on users, including patients, physicians, and other members of the care team who use the technology. In 2018, AHRQ funded 28 new research projects to address the important priority areas described below. The importance of select recently funded research projects are highlighted, including the goals of the research and anticipated outcomes or future potential application of the work. Select the hyperlink on the PI’s name for more information on the research.

### Advancing Research Evidence into Clinical Practice Through Clinical Decision Support

CDS helps clinicians, patients, and others on the care team by delivering the right information at the right time so they can make the best care decisions. When developed and implemented well, CDS uses patient-specific data and is guided by evidence-based findings to improve health and enable the best possible outcomes. AHRQ has a long history of investing in research about how to make CDS more effective, usable, and shareable.

The following is an example of exciting new CDS work funded in 2018:

- A team of clinicians, researchers, and informaticists from the MedStar Health Research Institute (https://healthit.ahrq.gov/ahrq-funded-projects/quantifying-efficiencies-gained-through-shareable-clinical-decision-support) is comparing CDS developed in isolation versus those developed using resources available on CDS Connect (https://cds.ahrq.gov/cdsconnect), a project funded by AHRQ to facilitate translation of evidence-based care into clinical practice with interoperable CDS. The implementation and testing will be conducted at four healthcare systems, representing different patient populations and two EHR vendors to facilitate a robust evaluation process. This systematic approach will allow for analytic comparisons within and across sites to identify efficiencies when using shareable and interoperable CDS resources.

### Using Patient-Reported Outcomes to Improve Patient Care

Incorporating brief, validated PRO measures into clinical care to assess outcomes, such as changes in symptoms, emotional health and wellbeing, and physical and social functioning, is essential to high-quality healthcare. Most PRO data are collected via pen and paper, which is difficult for patients, providers, and researchers to access and use. While some EHRs capture structured PROs, this information is not commonly collected and integrated at the point of care. AHRQ is at the forefront of funding innovative research to collect and use PROs leveraging health IT to improve patient care and wellbeing, as well as informing how to scale and spread existing health IT models. The following newly funded research incorporates PROs:

- Dr. Elsbeth Kalenderian (https://healthit.ahrq.gov/ahrq-funded-projects/optimizing-acute-post-operative-dental-pain-management-using-new-hit) and her research team at the University of California at San Francisco School of Dentistry are investigating the use of an app that collects a patient’s pain experience with the goal of reducing unnecessary opioid use in patients after dental surgery. Read the emerging research story here!
- Dr. Jinoos Yazdany (https://healthit.ahrq.gov/ahrq-funded-projects/rheumatology-informatics-system-effectiveness-patient-reported-outcome-rise-pro) at the University of California in San Francisco is leading research to extract PROs documented in clinical notes using NLP. The goal of the research is to unlock the potential of the information in clinical notes and use that information to create an evidence-based clinical learning network to support the participation of public hospital systems in PRO measurement and improvement efforts. Another goal is to make care more patient centered by developing tools that facilitate shared decision making and monitoring the care and treatment of patients with rheumatoid arthritis. Read the emerging research story here!
- The AHRQ Step Up App Challenge encouraged participants to create apps that advanced the collection of standardized PRO data in ambulatory care settings. Participants used draft technical specifications employing the HL7 Fast Healthcare Interoperability Resources (FHIR) Standards to develop user-friendly apps that enable PRO data to move between IT systems both within and across different providers. Research (https://healthit.ahrq.gov/ahrq-funded-projects/advancing-collection-and-use-patient-reported-outcomes-through-health) led by MedStar Health is modifying and pilot testing an application that incorporated the draft FHIR technical specifications to enable broader PRO data sharing for clinical and research purposes. In addition, the team will pilot test the winning app from the Step Up App Challenge.

### Using Artificial Intelligence to Improve Health and Healthcare

Artificial intelligence (AI), defined as the ability of computers to learn human-like functions or tasks, has shown great promise. What was previously considered the sole domain of human cognition is already being leveraged successfully across many industries, including healthcare. The rapid digitization of health data with health IT in the United States has created unprecedented opportunities in the use of AI in healthcare. The AHRQ Health IT Program is leading research efforts in this area including the following research:

- Dr. Michael Avidan (https://healthit.ahrq.gov/ahrq-funded-projects/anesthesiology-control-tower-feedback-alerts-supplement-treatment-actfast) and his research team at the Washington University School of Medicine are working to develop and evaluate an air traffic control-like command center for operating rooms. Anesthesiology Control Tower: Feedback Alerts to Supplement Treatment (ACTFAST) will apply data mining and machine learning to forecast adverse patient outcomes using data from the perioperative electronic medical record and real-time physiological data. The Anesthesiology Control Tower (ACT) will track and deliver alerts to anesthesiologists’ personal communication devices and enable expert clinicians located outside the operating room to provide attending anesthesiologists with real-time decision support.

### Learning Health Systems—Applying Data and Evidence to Improve Patient Care

Health systems that effectively apply data and evidence to improve patient outcomes and care are called learning health systems (LHSs). Gathering evidence on how best to utilize health IT to generate, integrate, and synthesize disparate data is a critical step toward supporting LHSs that continuously improve patient outcomes and care. AHRQ’s health IT program explores how health IT would best support LHSs, particularly in ambulatory care settings, including:

- Dr. Charles Friedman (https://healthit.ahrq.gov/ahrq-funded-projects/achieving-individualized-precision-prevention-ipp-through-scalable) from the University of Michigan and researchers from the Cleveland Clinic are using LHS methods to develop an application integrated within an EHR that is capable of automatically personalizing and prioritizing preventive measures for an individual using U.S. Preventive Services Task Force evidence-based recommendations to improve health.

### Engaging Patients and Families in Their Health Care

Research shows that patient and family engagement in healthcare leads to measureable improvements in safety, quality, and satisfaction of care. Health IT can facilitate patient engagement via the use of patient portals, social media, and tracking vitals or symptoms with wearable technology or mobile apps. Health IT also helps patients and their families more actively participate in their own health and wellness at any point of interaction with the healthcare system. Some funded health IT research projects that are targeting to improve patient and family engagement include:

- Dr. Carmela Alcantara (https://healthit.ahrq.gov/ahrq-funded-projects/using-ehealth-expand-access-cognitive-behavioral-therapy-insomnia-hispanic) from Columbia University is conducting research with non–English-proficient Hispanic patients with insomnia and behavioral health providers to develop a cultural adaptation of an existing cognitive behavioral therapy for insomnia program, an interactive program that can be delivered via tablet, smartphone, or computer and has been effective at reducing insomnia symptoms and co-occurring psychological symptoms. Read the emerging research story here!
- Dr. Mary Reed (https://healthit.ahrq.gov/ahrq-funded-projects/patient-choice-telemedicine-encounters) from the Kaiser Foundation Research Institute is conducting a study to understand who chooses telemedicine and for what health issues. The research also assesses whether telemedicine impacts the safety and quality of primary care by examining adherence to recommended healthcare guidelines and increased ED visits and hospital admissions. Kaiser Permanente Northern California began offering patient-initiated primary care telemedicine visits in 2016. All patients self-scheduling appointments with a primary care provider through their patient portal were able to choose from a traditional in-person visit or a telemedicine visit conducted by video or telephone. Read the emerging research story here!

The following stories exemplify in greater detail the innovative health IT that will be developed, implemented, and evaluated through the new research funded by AHRQ in 2018. The perspectives of the AHRQ-funded researchers are threaded into the following vignettes to elevate their novel methods and approaches for solving challenging problems facing the health system, fill gaps in knowledge, and respond to limitations of existing health IT.

### Using eHealth to Expand Access to Behavioral Healthcare for non-English-Proficient Hispanic Patients

Access to behavioral healthcare is often a challenge but is even more difficult for non–English-proficient patients to find bilingual behavioral providers who understand how culture affects patients’ interactions with the healthcare system. While cognitive behavioral therapy for insomnia (CBT-I) is an evidence-based alternative to medication, access is limited because of the lack of qualified bilingual behavioral health providers.

Cultural adaptation is the systematic process of modifying and adapting the intervention by integrating cultural components that align with patients’ worldview. Beyond language adaptations, it includes “deep structure” cultural adaptations such as changing examples to make them culturally relevant and avoiding Spanish language regionalisms.

#### Developing a cultural adaptation of an interactive digital program to deliver cognitive behavioral therapy for insomnia.

Dr. Carmela Alcantara, from Columbia University, is conducting research with non–English-proficient Hispanic patients with insomnia and behavioral health providers to develop a cultural adaptation of an existing digital CBT-I program. This intervention is an interactive program that can be delivered via tablet, smartphone, or computer that has been effective at reducing insomnia symptoms and co-occurring psychological symptoms.

Dr. Alcantara and her research team will conduct a randomized controlled trial with non–English-proficient Hispanic patients with chronic insomnia that compares the effectiveness of the culturally adapted digital version of CBT-I with enhanced usual care on reduction of insomnia symptoms.

Significance and Potential Impact: Adoption of this research will expand access to evidence-based alternatives to medication for the management of chronic insomnia and may narrow existing racial and ethnic disparities in access to high quality behavioral health care for patients.

PRINCIPAL INVESTIGATOR | Carmela Alcántara, Ph.D.
ORGANIZATION | Columbia University, New York, NY
RESEARCH TITLE AND PROFILE LINK | Using eHealth to Expand Access to Cognitive Behavioral Therapy for Insomnia in Hispanic Primary Care Patients (https://healthit.ahrq.gov/ahrq-funded-projects/using-ehealth-expand-access-cognitive-behavioral-therapy-insomnia-hispanic)

### Using Patient-Reported Data to Reduce Opioid Use in Dental Patients

#### Harnessing the power of patient-reported data using health IT.

Medical providers are increasingly using PRO data collected via mobile health applications for patient care; however, use of PRO data is largely unexplored in dentistry.

“Patient self-reporting is important for comprehensive pain assessment given pain’s subjective and multidimensional nature.”

- Dr. Elsbeth Kalenderian

Dentists often preemptively prescribe opioids when the use of non-opiate medications may be more appropriate. Post-op pain generally begins when the patient has returned home and anesthesia from the dental surgery wears off, making pain levels difficult to actively assess and manage. Typically, individuals experience post-op pain for only 3 days, leaving many patients with leftover pills. These remaining pills are a potential source of drug diversion—the transfer of a legally prescribed controlled substance from the individual for whom it was prescribed to another person for any illicit use—and thus a potential contributor to the opioid crisis.

Dr. Elsbeth Kalenderian, of the University of California San Francisco School of Dentistry and Harvard School of Dental Medicine, with Dr. Muhammad Walji, from the School of Dentistry at the University of Texas Health Science Center at Houston, are leading a team of researchers to study whether pain intensity data collected from patients after dental procedures can help dental providers track patients’ pain more effectively in real time and modify prescription use. Through a user-centered design process, the team is conducting usability testing and workflow analyses with providers and patients to adapt and customize the user interface of an existing mobile health platform called FollowApp.Care. Using a cluster-randomized experimental study, the team will then evaluate the impact of using mobile health technology on patients’ post-op pain experiences and oral health outcomes, as well as provider acceptance of it and its impact on provider performance.

Significance and Potential Impact: Actively tracking patient-reported symptoms should decrease the number of patients who are prescribed opioids after surgery upon discharge, as well as the strength of the opioid and length of time they are prescribed.

PRINCIPAL INVESTIGATOR | Elsbeth Kalenderian, DDS, MPH, PhD
ORGANIZATION | University of California at San Francisco School of Dentistry
RESEARCH TITLE AND PROFILE LINK | Optimizing Acute Post-Operative Dental Pain Management Using New Health Information Technology (https://healthit.ahrq.gov/ahrq-funded-projects/optimizing-acute-post-operative-dental-pain-management-using-new-hit)

### Why Do Patients Choose Telemedicine for Primary Care? The Untapped Potential of Telemedicine for Primary Care

#### Why do patients choose telemedicine as an alternative to an in-person primary care visit?

Telemedicine has long been used to provide access to specialty care, especially for patients living in rural areas, but its use to benefit primary care patients is less understood. In addition, little is known about its impact on quality and safety, such as on diagnoses, medications, or patient monitoring.

In 2016, Kaiser Permanente Northern California began offering patient-initiated primary care telemedicine visits. All patients self-scheduling appointments with a primary care provider through their patient portal were able to choose from a traditional in-person visit or a telemedicine visit conducted by video or telephone. Mary Reed, DrPH, from the Kaiser Permanente Northern California Division of Research, wants to know who chooses telemedicine and for what health issues. Dr. Reed and her team are prospectively comparing outcomes for patients who choose telemedicine versus an in-person primary care visit from 2016 to 2020. The research team will compare patient demographics, their reported experiences, and clinical characteristics, with the goal of identifying patterns or reasons why patients choose telemedicine versus an in-person visit. In addition, the team will evaluate whether telemedicine affects the safety and quality of primary care by examining recommended health care processes, in-person followup care, and increased ED visits and hospital admissions between those who choose telemedicine visits compared with those who choose an in-person visit.

“As a health services researcher, this was an exciting opportunity to research technology and how it affects patients’ choices, what kinds of clinical concerns patients choose telemedicine for, and what its best uses are for in primary care.”

- Dr. Mary Reed

Significance and Potential Impact: This research will provide evidence to inform emerging telehealth policies including reimbursement, technology adoption decisions, and real-world use by patients and providers.

PRINCIPAL INVESTIGATOR | Mary Reed, DrPH.
ORGANIZATION | Kaiser Foundation Research Institute; Kaiser Permanente Northern California Division of Research
RESEARCH TITLE AND PROFILE LINK | Patient Choice of Telemedicine Encounters (https://healthit.ahrq.gov/ahrq-funded-projects/patient-choice-telemedicine-encounters)

### Unlocking the Potential of PROs in Clinical Notes for Treating Rheumatoid Arthritis

Rheumatoid arthritis (RA) affects 1.3 million Americans, and those with low socio-economic status experience disparities in outcomes. PROs are used by rheumatologists to inform the care and treatment of patients with RA. Collection of this information is not standardized and, therefore, it cannot be reliably used for population health research. Furthermore, uninsured and minority patients are under-represented in health research, and RA research in particular. In a world where copious health data are collected, it is vital that these data represent the entire population.

#### Using natural language processing to drive quality improvement for rheumatoid arthritis care and treatment.

Dr. Jinoos Yazdany at the University of California in San Francisco is leading research to extract PROs documented in clinical notes using NLP. As the work progresses, the team will focus their efforts on aggregating RA PROs from participating public hospitals into a database that will be used to track improvements to agreed-upon measures. Dr. Yazdany’s research is aligned with AHRQ’s priority areas of patient-centered outcomes research and reducing health disparities among racial and ethnic minorities. Using NLP to aggregate PROs in clinic visit notes at public hospitals provides an opportunity to improve rheumatology care and treatment, particularly for vulnerable populations that experience the most health disparities. If successful, this research has the potential to transform healthcare for RA by making care more patient centered and by providing tools to facilitate shared decision making and disease monitoring.

Significance and Potential Impact: Use of NLP and PROs has the potential to transform the care of patients with RA, and to reduce health disparities for underserved and minority populations.

PRINCIPAL INVESTIGATOR | Dr. Jinoos Yazdany
ORGANIZATION | University of California at San Francisco
RESEARCH TITLE AND PROFILE LINK | Rheumatology Informatics Systems for Effectiveness Patient-Reported Outcome (RISE PRO) Dissemination Project (https://healthit.ahrq.gov/ahrq-funded-projects/rheumatology-informatics-system-effectiveness-patient-reported-outcome-rise-pro)