# I INTRODUCTION

## A About AHRQ Health IT Research

The Agency for Healthcare Research and Quality (AHRQ) is the lead Federal agency charged with improving the quality and safety of America's healthcare system. AHRQ invests in evidence-generating research and translates research findings into practice to achieve the following goals:

1. Keep patients safe and improve their health.
2. Help health professionals improve healthcare quality.
3. Generate data to track, evaluate, and improve the healthcare system.

The AHRQ Health Information Technology (IT) Program supports AHRQ’s mission by funding and disseminating research about how health IT can be used to improve the quality, safety, and efficiency of healthcare. While information technologies have reduced costs, improved the quality of services, and created transformational change in many industries, the healthcare industry was a late adopter of IT and has not yet realized its full benefit. AHRQ’s Health IT Program is producing and disseminating evidence-based research about optimizing the use of health IT to improve the quality, safety, and efficiency of healthcare. AHRQ’s Health IT Program invests in research grants and contracts awarded to researchers working across the country.

## B About This Report

This Year in Review report summarizes the research activities and outcomes funded by the AHRQ Health IT Program in 2018. The objective of this report is to support AHRQ stakeholders, including patients, clinicians, researchers, and policymakers, to:

- Learn about the goals of Health IT Program-funded research.
- Discover the innovative health technologies developed and tested by AHRQ-funded researchers, including new and emerging research in 2018.
- Understand how the Health IT Program improves healthcare quality and safety at the patient, provider, and health systems levels.
- Access learnings and products disseminated by AHRQ’s health IT-funded researchers in support of knowledge transfer and replication of successful health IT strategies that improve patient safety and healthcare quality.