# Acknowledgments

Specifically, we want to thank and recognize:

- Agency for Healthcare Research and Quality (AHRQ) leadership team, including Dr. Edwin Lomotan, Steve Bernstein, Shafa Al-Showk, and Mary Nix
- Clinical Decision Support (CDS) Connect Work Group members
- Oregon Community Health Information Network (OCHIN) Pilot Project Team
- Pilot site leadership and clinician end users
- MITRE CDS Connect Project Team