# Conclusion

Pilot implementation of a CDS artifact in a live clinical setting provides valuable opportunities to enhance the CDS specifications—not just for the distinct pilot implementation, but also for subsequent end users. Enhancements to the CDS occur along the entire continuum of pilot implementation, enabling iterations of the artifact to improve the reliability, validity, and usefulness of the CDS. The information in this document provides transparency on the findings, decisions, and lessons learned during the pilot use of the Pain Management Summary CDS specifications to inform future CDS development, enhancement, and implementation efforts.