# Lessons Learned and Broader Implications

Many of the findings outlined in this document have implications beyond the scope of the Pain Management Summary CDS artifact, impacting other CDS and electronic Clinical Quality Measurement (eCQM) developers and implementers as well. Approaches taken to address some of the constraints encountered during the pilot of the Summary CDS may inform other efforts and highlight opportunities for community engagement and effort in the future.

## Availability of Standard Codes

Standards-based, interoperable CDS is dependent upon the availability of standardized codes to express the clinical data elements required in the logic. Terminologies such as LOINC, SNOMED-CT, ICD10 and RxNorm provide a wealth of codes for CDS developers to use in their CDS expression. If codes are not available for the express need of a concept, developers are forced to use local codes to express the concept, lessening the interoperability of the final coded artifact.

Developers can submit applications for codes to be assigned to required concepts. MITRE did this for the PEG and STarT Back screening tools and anticipates that LOINC codes to express each aspect of these tools will be released in the December 2018 LOINC update. LOINC representatives are currently expanding representation of pain and opioid risk assessments as LOINC codes, and welcome community involvement in this effort.

## Intellectual Property Constraints

Many pain and risk assessments have intellectual property (IP) restrictions governing how their body of work may be used. Expression of their work as CDS and assignment of standard terminology codes to their work requires expressed permission. CDS developers should be aware of this requirement and respect IP regulations.

Application for new terminology codes (at least using the LOINC terminology), requires IP approval from the author of the assessment. LOINC representatives are willing to assist with author engagement to facilitate approval.

## Evaluating EHR Data for Evidence of Procedures and Treatments in a Primary Care Setting

Procedures and treatments rarely occur in a primary care setting; therefore, evidence of the treatment being performed or completed is usually not available in their EHR. Alternative approaches, such as looking at orders or referrals, can help identify some evidence of these concepts; however, limitations exist with this approach also (i.e., some treatments do not require an order or referral, such as “stretching” or “exercise”).

CDS developers and implementers should evaluate data availability and accuracy constraints before undertaking an effort and clearly convey the limitations of the CDS interventions to their end users for appropriate interpretation of the presented information.

## Need for Mapping

The need to map local codes to standard terminologies is likely to persist for the foreseeable future. As mentioned above, evaluation of if and how data is captured in a structured format in an EHR is one of the first steps in determining the feasibility of developing reliable CDS. If the required data is routinely captured in a structured field, but not recorded using a standard terminology, mapping the local code to the standard code expressed in the CDS is required. Implementation efforts should include an investigation of how the required data is captured in their system to inform the implementation timeline and identification of staff resources to assist with any mapping.

## Date of Diagnosis Accuracy

EHRs consistently capture the date that a new diagnosis is entered in the system. Often, that date is displayed and stored as the “onset date,” which may be a misrepresentation of the date. This is a significant limitation for CDS logic that evaluates the “onset date” of a Condition to provide guidance on an evidence-based treatment. Caution is required when evaluating this concept. Including the “asserted date” in the CDS provides context to the date presented as the “onset date.”