# Potential Future Enhancements of the CDS Artifact

Pain Management Summary CDS specifications enabled reliable and accurate delivery of CDS interventions to the intended population of patients at the pilot site. The specifications can be implemented at any time in other settings and EHRs (given successful integration and test results). Nevertheless, there are numerous ways that the specifications might be enhanced by developers and implementers in the future. Suggestions include:

- Develop a value set to represent non-pharmacologic treatment referrals to eliminate the need for mapping to the non-pharmacologic treatment value set.
- Develop value sets that represent a broader range of pain intensity assessments, multi-dimensional pain assessments, and opioid risk assessments once LOINC codes are available for the evidence-based assessments.
- Develop logic to express patient goals and pertinent attributes once the FHIR resource for Goals is more mature, transfer of goal-related data can pass through the FHIR interface, and standard terminology codes (e.g., LOINC and Systematized Nomenclature of Medicine-Clinical Terms [SNOMED-CT]) are available to express goal-related questions and responses related to pain. Note: This will only work if goal-related data is routinely captured in structured fields in the EHR. In addition, ideally, goals would be associated with a Condition expressed with a standard terminology code.
- Incorporate a MME calculator in to the logic, if not already available in the EHR. CDS specifications for an MME calculator are available on the CDS Connect Repository, via this link: https://cds.ahrq.gov/cdsconnect/artifact/cdc-opioid-prescribing-guideline-recommendation-5.
- Incorporate Prescription Drug Monitoring Program (PDMP) data if legal, security and technical constraints can be addressed.
- Develop CDS logic to generate directive guidance (e.g., an order set) derived from the CDC guidelines. Note: Logic exists in the SMART on FHIR app to generate flag notifications to draw attention to concerning summary entries. Logic to generate notifications is not included in the CQL.
- Adjust CDS specification to generate reports that can be reviewed by medical directors and clinicians outside of an encounter.
- Incorporate end user feedback obtained through pilot focus group discussions to enhance the usability and function of the artifact.