# Semi-Structured Representation of the Enhanced Artifact

The final semi-structured representation of the Pain Management Summary artifact incorporates all enhancements discussed in this document. Table 7 contains the inclusion and exclusion statements, and Table 8 contains the intervention logic.

Table 7 Final semi-structured inclusion and exclusion logic

Inclusions | Exclusions
Age >=18 years; AND; - OR Conditions associated with chronic pain (confirmed, active or recurring status, onset date, asserted date, abatement date); - OR Opioid pain medication; ○ Orders (date, active, completed, or stopped within past 180 days); ○ Statements (date, active, or completed within past 180 days); - OR Adjuvant analgesic medication; ○ Orders (date, active, completed, or stopped within past 180 days); ○ Statements (date, active, or completed within past 180 days) | None.

Table 8 Final semi-structured CDS intervention logic

POPULATE Pain Management Summary
Pertinent Medical History (unrestricted lookback):; - Conditions associated with chronic pain (confirmed, active or recurring status, onset date, asserted date, abatement date); - Risk factors for opioid-related harm; ○ Risk Conditions (represented by a union of value sets) - (confirmed, active or recurring status, onset date, asserted date, abatement date); ○ Encounter Risk Diagnosis (represented by a union of value sets) - (name, visit date, onset date, abatement date, and recorded date); ○ Pregnancy Observation in the past 42 weeks; ○ Age >=65 years
Pain Assessments (lookback of 2 years):; - Wong-Baker FACES Assessment (score, interpretation, date); - PEG Assessment (question response and total score, interpretation, date); - STarT Back Screening Tool (total score, interpretation, date)
Historical Treatments (lookback of 2 years for all except stool softeners, which is 6 months):; - Opioid pain medication; ○ Orders (date, active, completed, or stopped); ○ Statements (date, active, or completed); - Non-opioid pain medication; ○ Orders (date, active, completed, or stopped); ○ Statements (date, active, or completed); - Non-pharmacologic treatment; ○ Orders (date, accepted, in progress, or completed); ○ Referrals (date); - Stool softener and laxative; ○ Orders (date, active, completed, or stopped); ○ Statements (date, active, or completed)
Risk Considerations:; - MME calculation (most recent, verified, value [as quantity], date in past 6 months); - Urine drug screen (verified, result, interpretation, date in past 1 year); - Benzodiazepines medication; ○ Orders (date, active, completed, or stopped in the past 2 years); ○ Statements (date, active, or completed in the past 2 years); - Naloxone medication; ○ Orders (date, active, completed, or stopped); ○ Statements (date, active, or completed); - Risk assessments relevant to pain management (represented by a value set) - (total score, range, interpretation, date in past year); ○ Verified “single question r/t alcohol use” Observation; ○ Verified “single question r/t drug use” Observation
DISPLAY link to the CDC Guideline for Opioid Prescribing for Chronic Pain (https://www.cdc.gov/mmwr/volumes/65/rr/rr6501e1.htm)
DISPLAY Notice header: “TAKE NOTICE: This summary is not intended for patients who are undergoing end-of-life care (hospice or palliative) or active cancer treatment.”