# Artifact Enhancements

The Pain Management Summary specifications were enhanced by the MITRE team at three different points of the pilot partnership. Changes occurred during the “planning,” “integration,” and “testing” stages of the pilot. Each set of enhancements led to a richer, more informed and effective artifact. This section of the report outlines the list of changes made to the logic.

## Enhancements Made During Pilot Planning Sessions

Implementation of CDS in a clinical setting requires a significant amount of planning and coordination—especially when the CDS was developed outside the clinical organization where it is piloted. Vendor systems vary in the structured fields that they offer, and documentation practices vary by clinical site. Each implementation instance is bound to require small adjustments to the coded logic to accommodate these differences.

The changes in this section resulted from discussions attended by clinicians, informaticists, engineers, data analysts, and SMEs from CDC, OCHIN, and MITRE, during which the intent of the CDS, the logic, and each data requirement was thoroughly examined in comparison to how the data is captured in OCHIN’s system and provider workflow in a primary care encounter.

### Enhancements Informed by CDC Knowledge Stewards and OCHIN Clinicians and System Engineers

Since UI display of the Summary CDS via the SMART on FHIR app incorporates “flags” to draw the clinician’s eye to entries of concern based upon CDC recommendations, the CDC knowledge stewards urged alignment to components of their guidelines that were not formerly expressed in the CDS logic to ensure accurate translation of their evidence. The clinical concepts, concerns, enhancements, and commentary are outlined in Table 3.

Table 3 Enhancements made to align with the CDC guideline

Clinical Concept | Concern and Enhancement | Comments
Age >=18 years (Inclusion logic) | The CDC guideline explicitly states that it applies to patients aged >= 18 years. Applying the recommendations outside that population is not evidence-based.; Implementation Decision: Add to logic statement. | The MITRE team chose to implement this criteria in the inclusion logic (i.e., >=18 years old), as opposed to the exclusion logic (e.g., < 18 years old), since there are no other exclusion statements in the logic.
End-of-life care (Exclusion potential) | The CDC guideline does not apply to patients receiving end-of-life care (also described as hospice care and palliative care).; Implementation Decision: Display a Notice at the top of the summary that reminds clinicians that the CDS does not apply to individuals undergoing end-of-life care and ensure proper training regarding this Notice.; The Notice reads: “Take Notice: This summary is not intended for patients who are undergoing end-of-life care (hospice or palliative) or active cancer treatment.” | This concept was considered as a potential exclusion; however, system engineers and clinicians at the pilot site conveyed that evidence of this care (e.g., performed care, an order, or referral) is not routinely available in their system. Therefore, including the concept in CDS logic would likely generate interventions that are not appropriate for the patient. With CDC agreement, the cross-organizational team determined that displaying a Notice in the heading of the summary was the best way forward.
Active cancer treatment (Exclusion potential) | The CDC guideline does not apply to patients receiving active cancer treatment.; Implementation Decision: Display a Notice at the top of the summary that reminds clinicians that the CDS does not apply to individuals undergoing end-of-life care and ensure proper training regarding this Notice.; The Notice reads: “Take Notice: This summary is not intended for patients who are undergoing end-of-life care (hospice or palliative) or active cancer treatment.” | This concept was considered as a potential exclusion; however, system engineers and clinicians at the pilot site conveyed that evidence of active cancer treatment (e.g., completed treatments, an order for cancer treatment) is not available in their system. Including “active cancer treatment” in the logic might generate inappropriate interventions for the patient since the logic cannot evaluate data captured at clinical sites outside of the pilot organization. With CDC agreement, the cross-organizational team determined that displaying a Notice in the heading of the summary was the best way forward.
Risk factors for opioid-related harms (Intervention logic) | Several CDC recommendations include the need to evaluate for risk factors prior to initiating opioid therapy. Risk factors outlined in the guideline include: depression, anxiety, substance use disorder, suicide attempt, sleep-disordered breathing, renal dysfunction, hepatic dysfunction, pregnancy, age >=65. Including evidence of this information in the Summary would provide great value, since prescribing opioids to these individuals could increase their risk for harm.; Implementation Decision: Add to the intervention logic. | MITRE chose to incorporate these concepts in the following way:; - A new data element was added to the intervention logic (i.e., risk factors for opioid-related harms); - The data element was expressed as a union of value sets defining each of the Conditions (e.g., depression, anxiety), with additional logic to express age >=65.; - This new data element was added to the Pertinent Medical History category of the Summary.

In addition, the CDC program office responsible for the guideline suggested including a list of stool softeners and laxatives in the Historical Treatment section of the Summary to assist clinicians in managing constipation, a common side effect of opioid therapy. OCHIN concurred with this suggestion, and MITRE added logic to express this concept and display the results to the Historical Treatment section of the CDS.

### Enhancements Made in Collaboration with OCHIN Clinicians and System Engineers

Many refinements were made to the CDS logic and coded expression of clinical concepts during planning sessions held at the outset of pilot collaboration. The clinical concepts, concerns, and rationale for CDS specification changes are outlined below in Table 4.

Table 4 Enhancements made in collaboration with the pilot site

Clinical Concept | Concern and Enhancement | Comments
Add “asserted date” and “abatement date” elements to all Conditions (Inclusion and intervention logic) | The CDS logic originally queried for and displayed the “onset date” for all Conditions; however, often the “onset date” reflects the date the Condition was entered in to the patient record, as opposed to the date the patient was diagnosed with a Condition. Adding the “asserted date” (i.e., recorded date) provides context to the “onset date.” “Abatement date” was included as additional information and to balance the UI in the SMART on FHIR app across all the data elements.; Implementation Decision: Add the “asserted date” and “abatement date” to logic statements. | Accurate, structured capture of the diagnosis date is a common constraint across many healthcare organizations and EHR implementations. The “onset date” does not routinely reflect the date of diagnosis.; Note: The MITRE team used the “proper” FHIR element as described in this section but renamed each element in the SMART on FHIR app UI to provide clarity for providers. As such:; - The CQL specifies “onset date,” but the app displays “Start Date.”; - The CQL specifies “asserted date,” but the app displays “Date Recorded.”; - The CQL specifies “abatement date,” but the app displays “Stop Date.”
Adjuvant analgesic medications (Inclusion logic) | The “Non-opioid pain medication” data element in the inclusion logic may be too broad since it includes medications used as primary and secondary treatments for pain (e.g., anti-convulsant and anti-depressant medications in addition to analgesics).; Implementation Decision: The “Non-opioid pain medication” value set was replaced with the “Adjuvant analgesic medications” value set to constrain results to patients receiving a medication for the primary treatment of pain. | This was a subjective decision that weighed populating the Summary for as many patients with chronic pain as possible, while not populating the Summary for individuals who might be experiencing very mild, acute pain. Future implementers may choose to refine the logic to best serve their providers and patient population.
Lookback of 180 days (Inclusion criteria) | The expression was included to define how far back the logic should look for evidence of an opioid or adjuvant analgesic medication (otherwise any evidence of a medication in the past would have qualified the patient).; Implementation Decision: OCHIN concurred with the 180-day lookback period; however, this concept was expressed as a parameter, so subsequent implementers could adjust the period as needed. | This was another subjective decision that allowed a reasonable number of patients to evaluate positively against the logic.; Provider feedback after the pilot may inform potential adjustments to this lookback period moving forward (e.g., include duration of the prescription in the logic, along with the lookback).
Evaluate Encounter diagnosis as a secondary way of capturing “Risk factors for opioid-related harms” Conditions (Intervention logic) | OCHIN staff mentioned some Conditions listed in the “Risk factors for opioid-related harms” data element may be best captured as an encounter diagnosis.; Implementation Decision: Add logic to evaluate for evidence of encounter diagnosis for “Risk factor” Conditions also and include “visit date.” | This ensured that all relevant data was populated in the Summary. This addition may not be necessary in other healthcare settings.; Note: “onset date,” “abatement date,” and “recorded dates” are included in the result structure of this concept, but are always empty since encounters don’t carry those dates.
Pregnancy as an Observation (Intervention logic) | Some providers record Pregnancy as an Observation, as opposed to a Condition. OCHIN confirmed that this was a valid “back-up” approach to evaluate pregnancy status.; Implementation Decision: This logic was retained. | This was a “lessons learned” from the pilot partnership last year with a health center affiliate of Alliance (formerly AllianceChicago).
PEG Activity Tool – question scores (Intervention logic) | Since the PEG is comprised of questions that evaluate three very distinct aspects of a patient’s pain experience, there is value in displaying each individual response, along with the total score.; Implementation Decision: Add code to query for and display the individual scores. | Note: The same approach was not taken for the STarT Back Screening Tool, since that has nine questions, and responses would have overwhelmed the Summary UI.; In addition, proprietary (i.e., local) codes were used for all aspects of these assessments since Logical Object Identifier Names and Codes (LOINC) codes do not currently exist. Ideally, a LOINC code would be used to represent each assessment, their individual questions, and their total scores. MITRE submitted applications for LOINC codes to be assigned. LOINC representatives estimate that the new codes will be available in the December LOINC release.
Goals (Intervention logic) | Capturing patient goals and making decisions that help patients achieve their goals is tremendously important. It was not initially modeled in the logic since standard codes are not readily available to express the required information. If goal-related data was available in OCHIN’s system, local codes could have been used in the logic expression.; Implementation Decision: Do not include logic to express goals. | OCHIN staff conveyed that patient goals are rarely captured by clinicians in a structured format, at present. This is a challenging clinical concept to evaluate across other organizations also.; OCHIN shared that a quality improvement initiative is underway to facilitate regular structured capture of this information. Future enhancements in this area may be beneficial once the data are routinely available.
Lookback of 1 year for risk assessments (Intervention logic) | Initially the lookback was defined as 6 months; however, OCHIN’s CDS Physician Lead suggested expanding the lookback due to clinical practice, so as not to miss relevant assessment results.; Implementation Decision: Change code to specify a 1-year lookback. | This value set represents varied assessments to screen for depression, anxiety, opioid risk, alcohol use, and substance use.
Alcohol and Drug Screen single questions (Intervention logic) | OCHIN has two commonly used screening questions related to alcohol and drug use that are valid indicators of risk.; Implementation Decision: Add both screening questions to the logic. | Note: Both questions are represented by proprietary (i.e., local) codes, along with MME since standard codes are not currently available.; Once standard codes are issued for the concepts above, future implementers can update the CDS logic with the standard codes.

## Enhancements Made During CDS Integration

Integration of CDS in an EHR system is a large undertaking, often requiring custom development and configuration. For the purpose of this document, integration is scoped to efforts taken to identify how the required data is captured in OCHIN’s system versus how the data is used in the CDS. MITRE instituted enhancements when disconnects were identified between the logic expression and the EHR data to ensure robust data evaluation and the delivery of accurate CDS interventions.

Enhancements that occurred during this stage of the pilot effort are outlined in Table 5.

Table 5 Enhancements made during CDS integration

Clinical Concept | Concern and Enhancement | Comments
Assessment result ranges (Intervention logic) | Assessment tool authors often include an interpretation of assessment scores to provide context to the numeric score (e.g., a score of 4 may be interpreted as moderate pain). Although the CDS logic queries for the interpretation of each score, the interpretation was generally not present in the data returned through the FHIR interface; therefore, it would not display in the SMART on FHIR app. As a workaround to this problem, MITRE proposed adding the score ranges to the CQL code, to provide context to the score (e.g., a score of 4 on a scale of 0–10).; Implementation Decision: Add assessment score ranges to the logic. | Note: MITRE investigated developing code to convert a numeric score to the author’s interpretations of that score; however, legal counsel determined that intellectual property permissions were required to implement this approach, and the pilot timeline could not afford this delay (therefore, the approach was not implemented). Future implementers may choose to further investigate this approach.
Non-pharmacologic treatments – Referrals (Intervention logic) | Non-pharmacologic treatments are very difficult to identify in a structured format in EHRs. For instance, the treatment itself (e.g., physical therapy, yoga) does not occur in a primary care setting. Secondly, treatment orders are only placed for care that requires an order, putting structured data capture of the treatment in jeopardy (e.g., a physician is unlikely to order “stretching,” or yoga). As a result, query results likely include a fraction of the care discussed with a patient.; OCHIN technical staff identified an opportunity to evaluate referrals as evidence of non-pharmacologic treatments, improving the odds of displaying relevant treatments.; Implementation Decision: Relevant referrals in OCHIN’s system were mapped to non-pharmacologic codes in the MITRE-created value set. | Moving forward, implementers may choose to create a referral value set if standardized codes are available to express the indicated concepts.
Wong-Baker FACES Assessment (Intervention logic) | This assessment usually supports pain intensity ratings on a scale of 0–10. However, OCHIN provides the assessment with a scale of 0–5. Clear communication of the range is imperative to provide the clinician with the right interpretation context.; Implementation Decision: A unique branch of the CQL code was created for the OCHIN pilot to define the range as 0–5. | The branch of the codes released to the public includes the published 0–10 range.; Future implementers should double check their systems to ensure alignment to the ranges defined in the CQL.

## Enhancements Made During CDS Testing

Robust testing is integral to release accurate, reliable, valid CDS. Testing is conducted after integration of the CDS is complete, using first synthetic data and later “real” patient data. OCHIN’s synthetic records tested all logic phrases, attributes, and value sets, and included positive and negative testing. Only one issue identified during testing on the development server required a change to the CDS specification (outlined in Table 6). Testing on production with live patient data did not elicit the need for additional enhancements.

Table 6 Enhancements made during CDS testing in the EHR system

Clinical Concept | Concern and Enhancement | Comments
Conditions associated with chronic pain (Inclusion and intervention logic) | Testing revealed missing International Classification of Disease 10 (ICD10) codes in this value set (e.g., pain in “unspecified” knee).; Implementation Decision: Additional, indicated codes were added to the value set. | No additional concerns were raised about the value set definition.

## Enhancements Made During the Live CDS Pilot

Concerns that arose during the live pilot (e.g., latency) did not involve the CDS specifications. No additional enhancements were made to the artifact during live use of the CDS in a primary care setting.