# Initial Definition of the Pain Management Summary Artifact

## Description and Purpose of the Artifact

The Pain Management Summary artifact provides relevant information to consider when managing a patient’s pain; not only eliminating the need to navigate to and from the problem list, medication list, lab results, etc., for information, but also filtering all the entries in a patient record to only display concepts related to pain management. The populated summary is intended to promote discussion between the patient and the provider regarding the effectiveness of existing treatments, and the benefits and risks of future interventions while considering the use of non-opioid and/or non-pharmacologic treatment when possible.

## Initial Semi-Structured Representation of the CDS Logic

Development of the Summary CDS was informed by the Centers for Disease Control and Prevention (CDC) Guideline for Opioid Prescribing for Chronic Pain. The CDS is not a direct representation of any one recommendation statement within the guideline. Instead, the CDS compiles clinical concepts mentioned throughout the guideline in one consolidated view (i.e., the Summary) for clinician review. The CDS was developed by a multi-disciplinary team of clinicians, informaticists, and engineers. At no point during the life cycle of the CDS were rules included in the CQL to provide guidance on how to act upon the compiled information (e.g., alerts). Effective use of the CDS requires clinician training on the CDC guidelines, the scope of the CDS, and where clinical judgement is required.

Table 1 outlines the initial representation of the inclusion and exclusion logic, and Table 2 outlines the initial representation of the interventions generated by the CDS code.

Table 1 Initial semi-structured inclusion and exclusion logic

Inclusions | Exclusions
- Conditions associated with chronic pain (confirmed, active or recurring status, onset date); - OR Opioid pain medication; ○ Orders (active, completed, or stopped within past 180 days); ○ Statements (active or completed within past 180 days); - OR Non-opioid pain medication; ○ Orders (active, completed, or stopped within past 180 days); ○ Statements (active or completed within past 180 days) | None.

Table 2 Initial semi-structured CDS intervention logic

POPULATE Pain Management Summary
Pertinent Medical History (unrestricted lookback):; - Conditions associated with chronic pain (confirmed, active or recurring status, onset date)
Pain Assessments (lookback of 2 years):; - Wong-Baker FACES Assessment (score, interpretation, date); - Pain Enjoyment General Activity (PEG) Assessment (total score, interpretation, date)
Historical Treatments (lookback of 2 years):; - Opioid pain medication; ○ Orders (date, active, completed, or stopped within past 180 days); ○ Statements (date, active, or completed within past 180 days); - Non-opioid pain medication; ○ Orders (date, active, completed, or stopped within past 180 days); ○ Statements (date, active, or completed within past 180 days); - Non-pharmacologic treatment; ○ Orders (date, accepted, in progress, or completed)
Risk Considerations:; - Morphine milligram equivalent (MME) calculation (most recent, verified, value [as quantity], date in past 6 months); - Urine drug screen (verified, result, interpretation, date in past 1 year); - Benzodiazepines medication; ○ Orders (date, active, completed, or stopped in the past 2 years); ○ Statements (date, active, or completed in the past 2 years); - Naloxone medication; ○ Orders (date, active, completed, or stopped); ○ Statements (date, active, or completed); - Risk assessments relevant to pain management (total score, range, interpretation, date in past 6 months)
DISPLAY link to the CDC Guideline for Opioid Prescribing for Chronic Pain (https://www.cdc.gov/mmwr/volumes/65/rr/rr6501e1.htm)