# Introduction

The Agency for Healthcare Research and Quality (AHRQ) has elected to sponsor the Clinical Decision Support (CDS) Connect project to generate a systematic and replicable process for transforming patient-centered outcomes research (PCOR) findings into shareable and standards-based CDS artifacts. A CDS artifact is the template for defining how decision support is provided for a given clinical situation, often including triggers, logic, operations, interventions, and supporting evidence. The CDS Connect Repository was created to host and share CDS artifacts, and the CDS Authoring Tool enables CDS developers to create CDS using a standard expression language and terminologies. Both systems contribute to AHRQ’s mission of advancing evidence-based research into clinical practice using CDS artifacts, ultimately integrated with a clinical site’s electronic healthcare record (EHR).

## Background

CDS specifications undergo numerous iterations from the moment an artifact is conceived through development, integration, testing, and implementation of the CDS in a clinical environment. Iterations and enhancements are key to the artifact’s use and effectiveness. This document outlines changes made to the semi-structured and structured representations of the Factors to Consider When Managing Chronic Pain: A Pain Management Summary CDS artifact (hereinafter, Pain Management Summary or Summary), during engagement with Oregon Community Health Information Network (OCHIN), the organization that piloted the artifact.

OCHIN is one of the largest health information and innovation networks in the United States, serving hundreds of organizations by delivering health information technology support and services^1^. From March 2018 through August 2018, MITRE and OCHIN partnered on the implementation of the Pain Management Summary CDS in OCHIN’s Epic EHR environment. Both organizations collaborated on refinements to the CDS during every stage of the partnership to improve the accuracy and usefulness of the CDS. Changes were made based on:

- subject matter expert (SME) feedback
- organizational initiatives, process, and policy
- data structure and availability
- technical findings
- integration constraints
- test results
- clinician feedback.

Details in this document were recorded to provide transparency on the fine-tuning required to implement CDS specifications in a clinic site’s EHR. CDS developers working to express similar clinical concepts may find this information instructive, and future “implementers” may value the breakdown by data element and logic specification to pinpoint where they might like to adjust or enhance the artifact further.

Revisions and improvements to the CDS specifications are outlined in the Artifact Enhancement section of the document.

## Scope

This document catalogs all enhancements made to the clinical quality language (CQL) code during the pilot partnership. It does not include enhancements to the CQL integration engine (i.e., the Substitutable Medical Applications, Reusable Technologies [SMART] on Fast Healthcare Interoperability Resources [FHIR] application), which also enabled the user interface (UI) for the CDS. The CDS Connect Pilot Report provides detailed information with regards to the CQL integration engine.

1 We are OCHIN. About Us. Accessed on August 8, 2018 at: https://ochin.org/about-us/.