# 9 References

[1] Murray CJ, Atkinson C, Bhalla K, . (2014) The state of US health, 1990-2010: Burden of diseases, injuries, and risk factors. Jama. Aug 14 2013;310(6):591–608.
[2] Institute for Health Metrics and Evaluation. (ND) Retrieved from http://www.healthdata.org/united-states.
[3] Institute of Medicine Committee on Advancing Pain Research, Care Education. The National Academies Collection: Reports funded by National Institutes of Health. Relieving pain in America: A blueprint for transforming prevention, care, education, and research. Washington (DC): National Academies Press (US); 2011
[4] American Academy of Pain Medicine. AAPM Facts and Figures on Pain. Retrieved at http://www.painmed.org/PatientCenter/Facts_on_Pain.aspx
[5] Daubresse M, Chang HY, Yu Y, . (2013) Ambulatory diagnosis and treatment of nonmalignant pain in the United States, 2000-2010. Med Care. Oct 2013;51(10):870–878.24025657
[6] Reuben DB, Alvanzo AAH, Ashikaga T, . (2015) National Institutes of Health Pathways to Prevention workshop: The role of opioids in the treatment of chronic pain the role of opioids in the treatment of chronic pain. Annals of Internal Medicine. 2015;162(4):295–300.25581341
[7] U.S. Department of Health and Human Services. (2016) National Pain Strategy Outlines Actions for Improving Pain Care in America. Retrieved from https://www.hhs.gov/ash/about-ash/news/2016/national-pain-strategy-outlines-actions-improving-pain-care/index.html
[8] The White House. (2017) President Donald J. Trump is Taking Action on Drug Addiction and the Opioid Crisis. Retrieved from https://www.whitehouse.gov/the-press-office/2017/10/26/president-donald-j-trump-taking-action-drug-addiction-and-opioid-crisis
[9] Department of Veterans Affairs, Department of Defense. (2017) VA/DoD Clinical Practice Guideline for Opioid Therapy for Chronic Pain Version 3.0. Retrieved from https://www.healthquality.va.gov/guidelines/Pain/cot/VADoDOTCPG022717.pdf
[10] Dowell D, Haegerich TM, Chou R. CDC Guideline for Prescribing Opioids for Chronic Pain — United States, 2016. MMWR Recomm Rep 2016;65(No. RR-1):1–49. DOI: 10.15585/mmwr.rr6501e1.
[11] American Society for Addiction Medicine. (2014) The ASAM Performance Measures for the Addiction Specialist Physician. Retrieved from https://www.asam.org/docs/default-source/advocacy/performance-measures-for-the-addiction-specialist-physician.pdf?sfvrsn=5f986dc2_0
[12] Centers for Disease Control and Prevention. (2017) Opioid Prescribing Support Implementation Guide. Retrieved from http://build.fhir.org/ig/cqframework/opioid-cds/
[13] Indian Health Service. Proper Pain Assessment. Retrieved from https://www.ihs.gov/painmanagement/properpatientassessment/
[14] National Association of Attorneys General. (2017) Opioid Letter to AHIP. Retrieved from https://ag.ny.gov/sites/default/files/final_naag_opioid_letter_to_ahip.pdf
[15] Rudd RA, Seth P, David F, Scholl L. Increases in Drug and Opioid-Involved Overdose Deaths — United States, 2010–2015. MMWR Morb Mortal Wkly Rep. 2016;65. doi:10.15585/mmwr.mm655051e1.
[16] The Washington Post. (August 11, 2017). How to Comfort the Opioid Emergency. Retrieved from https://www.washingtonpost.com/opinions/how-to-confront-the-opioid-emergency/2017/08/11/f8ef4220-7dd5-11e7-b2b1-aeba62854dfa_story.html?utm_term=.e3c7d5575d48
[17] Florence CS, Zhou C, Luo F, Xu L. The Economic Burden of Prescription Opioid Overdose, Abuse, and Dependence in the United States, 2013. Med Care. 2016;54(10):901–906. doi:10.1097/MLR.0000000000000625.27623005
[18] The White House. (2017) National Drug Control Strategy. Retrieved at https://obamawhitehouse.archives.gov/ondcp/policy-and-research/ndcs
[19] Centers for Disease Control and Prevention (2016) Morbidity and Mortality Weekly Report: Increases in Drug and opioid Overdose Deaths – United States, 2000-2014. Retrieved from: https://www.cdc.gov/mmwr/preview/mmwrhtml/mm6450a3.htm
[20] Centers for Disease Control and Prevention. (2017) Prescribing Data. Retrieved from https://www.cdc.gov/drugoverdose/data/prescribing.html
[21] Harvard Law & Policy Review. (2017) The Opioid Epidemic: Fixing a Broken Pharmaceutical Market. Retrieved from http://harvardlpr.com/wp-content/uploads/2017/07/SarpatwariSinhaKesselheim.pdf
[22] National Center for Biotechnology Information. (2013) Pain as the 5^th^ Vital Sign: Exposing the Vital Need for Pain Education. Retrieved from https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3888154/
[23] Centers for Disease Control and Prevention: Morbidity and Mortality Weekly Report. (2016) CDC Guideline for Prescribing Opioids for Chronic Pain. Retrieved from https://www.cdc.gov/mmwr/volumes/65/rr/pdfs/rr6501e1er.pdf
[24] National Center for Biotechnology Information. (2011) Management of Chronic Pain in the Rheumatic Diseases with Insights for the Clinician. Retrieved from https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3382677/
[25] Centers for Disease Control and Prevention. (ND) Nonopioid Treatments for Chronic Pain. Retrieved from: https://www.cdc.gov/drugoverdose/pdf/nonopioid_treatments-a.pdf
[26] National Center for Biotechnology Information. (2008) Pain Management in Musculoskeletal Conditions. Retrieved from https://www.ncbi.nlm.nih.gov/pubmed/18519099
[27] Institute of Medicine (US) Committee on Quality of Health Care in America. Crossing the Quality Chasm: A New Health System for the 21st Century. (2001). Retrieved from https://www.ncbi.nlm.nih.gov/books/NBK222265/#ddd00039
[28] Robinson, J.H., Callister, L.C., Berry, J.A., and Daring, K.A. (2008). Patient-centered care and adherence: Definitions and applications to improve outcomes. J of the American Academy of Nurse Practitioners 20(12) pg 600–607. Retrieved from http://onlinelibrary.wiley.com/doi/10.1111/j.1745-7599.2008.00360.x/abstract
[29] Rathert, C., Wyrwich, M.D., & Born, S.A. (2012). Patient-Centered Care and Outcomes: A Systematic Review of the Literature. Retrieved from http://journals.sagepub.com/doi/abs/10.1177/1077558712465774?journalCode=mcrd
[30] Stewart M., Brown J.B., Donner A, McWhinney JR, Oates J, Weston WW & Jordan J. (2000). The impact of patient-centered care on outcomes. Journal of Family Practice. 49(9):796–804. Retrieved from https://www.ncbi.nlm.nih.gov/pubmed/11032203 11032203
[31] Centers for Medicare and Medicaid Services: Innovation Center New Direction. Request for Information (September 20, 2017). Retrieved from https://innovation.cms.gov/initiatives/direction/
[32] Greene SM, Tuzzio L, & Cherkin, D. (2012) A Framework for Making Patient-Centered Care Front and Center. The Permanente Journal. 16(3) 49–53. Retrieved from https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3442762/ 23012599
[33] Inflexxion. (N.D.) PainCAS: A Scientifically Developed Tool for Pain and Opioid Risk Assessment. Retrieved from https://www.inflexxion.com/paincas/
[34] National Institute of Drug Abuse. (2016) Clinical decision support for Opioid use disorders in Medical settings: Pilot Usability Testing in an EMR (COMPUTE). Retrieved from https://www.drugabuse.gov/about-nida/organization/cctn/ctn/research-studies/clinical-decision-support-opioid-use-disorders-in-medical-settings-pilot-usability-testing-in-emr
[35] Clinical Pain Advisor. (2015). CHOIR Integrates Clinical Decision Support into EHRs for Chronic Pain. Retrieved from http://www.clinicalpainadvisor.com/aps-2015/choir-integrates-clinical-decision-support-into-ehrs-for-chronic-pain/article/415113/
[36] Cedars-Sinai (N.D.) Patient Voices in Chronic Pain. Retrieved from https://www.cedars-sinai.edu/Research/Research-Areas/CORE/Patient-Voices-in-Chronic-Pain.aspx
[37] Centers for Disease Control and Prevention. (2015) Common Elements in Guidelines for Prescribing Opioids. Retrieved from http://pcss-o.org/wp-content/uploads/2015/12/Common_Elements_in_Guidelines_for_Prescribing_Opioids-a.pdf
[38] Graham R, Mancher M, Wolman DM, Greenfield S, Steinberg, E (Eds). (2011) Clinical Practice Guidelines We Can Trust. National Academies Press.
[40] Manchikanti L . Responsible, Safe, and Effective Prescription of Opioids for Chronic Non-Cancer Pain: American Society of Interventional Pain Physicians (ASIPP) Guidelines. Pain Physician. 2017 Feb;20(2S):S3–S92.28226332
[41] Institute for Clinical Systems Improvement. (2012) Adult Acute and Subacute Low Back Pain. Retrieved from https://www.icsi.org/guidelines__more/catalog_guidelines_and_more/catalog_guidelines/catalog_musculoskeletal_guidelines/low_back_pain/
[42] Institute for Clinical Systems Improvement. (2016) Pain: Assessment, Non-opioid Approaches and Opioid Management. Retrieved from https://www.icsi.org/guidelines__more/catalog_guidelines_and_more/catalog_guidelines/catalog_neurological_guidelines/pain/
[43] Qaseem, A., . (2017). “Noninvasive Treatments for Acute, Subacute, and Chronic Low Back Pain: A Clinical Practice Guideline From the American College of Physicians.” Ann Intern Med 166(7): 514–530.28192789
[44] Clinical Pharmacogenetics Implementation Consortium. (2014) Clinical Pharmacogenetics Implementation Consortium guidelines for cytochrome P450 2D6 genotype and codeine therapy: 2014 update. Retrieved from https://www.guidelines.gov/summaries/summary/47993/clinical-pharmacogenetics-implementation-consortium-guidelines-for-cytochrome-p450-2d6-genotype-and-codeine-therapy-2014-update?q=opioid
[45] Department of Veterans Affairs/Department of Defense. (2015) VA/DoD Clinical Practice Guideline for the Management of Substance Use Disorders. Retrieved from https://www.healthquality.va.gov/guidelines/MH/sud/VADoDSUDCPGFinal1.pdf
[46] Kampman, K. and M. Jarvis (2015). “American Society of Addiction Medicine (ASAM) National Practice Guideline for the Use of Medications in the Treatment of Addiction Involving Opioid Use.” J Addict Med 9(5): 358–367.26406300 CQM Section:
[47] National Committee for Quality Assurance. (2017) Retrieved from http://blog.ncqa.org/wp-content/uploads/HEDIS-HPA-2018-Google-Hangout-All-Slides-Final.pdf
[48] American Society for Addiction Medicine. (2014) The ASAM Performance Measures for the Addiction Specialist Physician. Retrieved from https://www.asam.org/docs/default-source/advocacy/performance-measures-for-the-addiction-specialist-physician.pdf?sfvrsn=5f986dc2_0
[68] Goertz M, Thorson D, Bonsell J, Bonte B, Campbell R, Haake B, Johnson K, Kramer C, Mueller B, Peterson S, Setterlund L, Timming R. (2012) Adult acute and subacute low back pain. Bloomington (MN): Institute for Clinical Systems Improvement (ICSI); Nov. 91 p.
[69] Hooten WM, Timming R, Belgrade M, Gaul J, Goertz M, Haake B, Myers C, Noonan MP, Owens J, Saeger L, Schweim K, Shteyman G, Walker N. (2013) Assessment and management of chronic pain. Bloomington (MN): Institute for Clinical Systems Improvement (ICSI); Nov. 105 p.
[70] American Medical Directors Association (AMDA). (2014) Implementing AMDA’s clinical practice guidelines in the long term care setting -- CPG implementation series: pain management manual. Columbia (MD): American Medical Directors Association; 113 p.
[71] Pharmacy Quality Alliance (PQA). (2015) Technical specifications for PQA approved measures. Springfield (VA): Pharmacy Quality Alliance (PQA); Jul. 66 p.
[72] American Society of Addiction Medicine. (2014) The ASAM Performance Measures for the Addiction Specialist Physician. Retrieved from https://www.asam.org/docs/default-source/advocacy/performance-measures-for-the-addiction-specialist-physician.pdf?sfvrsn=5f986dc2_0
[73] National Committee for Quality Assurance. (2017) HEDIS 2018 Volume 2: Technical Update. Retrieved from http://www.ncqa.org/Portals/0/HEDISQM/HEDIS2018/HEDIS%202018%20Volume%202%20Technical%20Update.pdf?ver=2017-10-01-234940-073
[49] Ballantyne JC, Fishman SM, Rathmell JP. (2009) Bonica’s management of pain. Philadelphia, PA: Lippincott Williams & Wilkins.
[50] Gatchel RJ, Peng YB, Peters ML, Fuchs PN, Turk DC. (2007) The biopsychosocial approach to chronic pain: Scientific advances and future directions. Psychol Bull. Jul 2007;133(4):581–624.17592957
[51] Department of Defense/Veterans Health Administration. Pain Management for Primary Care: Clinical Assessment of Pain/Assessment Tools. Module 3-2.
[52] Inflexxion. (2017) PainAction. Retrieved from https://www.painaction.com/
[53] Consumer Reports. (2016) Pain Management: Which Treatment is Right for You? Retrieved from https://www.consumerreports.org/pain-relief/pain-management-treatment-right-for-you/
[54] Inflexxion. (2017) PainEDU. Retrieved from https://www.painedu.org/
[55] Centers for Disease Control and Prevention. (ND) Nonopioid Treatments for Chronic Pain. Retrieved from https://www.cdc.gov/drugoverdose/pdf/nonopioid_treatments-a.pdf
[56] Department of Veterans Affairs. (2013) Mental Health Innovations Template – Pain. Accessed at: https://www.va.gov/PAINMANAGEMENT/docs/CIM_CAM_MH_INNOVATIONS_Pain_4_23_13.pdf
[57] Kahan, M., Srivastava, A., Wilson, L., Gourlay, D., & Midmer, D. (2006). Misuse of and dependence on opioids: Study of chronic pain patients. Canadian Family Physician, 52(9), 1081.17279218
[58] Studies Identify Riskiest Patients for Opioids. (2017) Retrieved from https://www.painnewsnetwork.org/stories/2017/4/14/studies-identify-riskiest-patients-for-opioids
[59] Walker MJ, Webster LR. Risk factors for drug diversion in a pain clinic patient population. (2012) Journal of Opioid Management. 2012; 8(6): 351–62. Retrieved from http://www.ncbi.nlm.nih.gov/pubmed/23264313 Accessed on: 2015-07-07.23264313
[60] Harry, E; Patel, R; Mlaver, E; Espares, J; Schnipper, JL. Building a Dashboard to Identify Patients at High Risk for Adverse Drug Events Related to Opioids [abstract]. Journal of Hospital Medicine. 2017; 12 (suppl 2). Retrieved from http://www.shmabstracts.com/abstract/building-a-dashboard-to-identify-patients-at-high-risk-for-adverse-drug-events-related-to-opioids/.
[61] Venebio Opioid Advisor. (2016) Retrieved from http://venebio.com/wp-content/uploads/2016/10/VOA-product-sheet.pdf
[62] CDC Opioid Guideline app, viewed on the iTunes app store 10/25/2017. Also retrieved from https://www.cdc.gov/drugoverdose/training/index.html
[63] Centers for Disease Control and Prevention. (2017) Checklist for Prescribing Opioids for Chronic Pain, modified June 21, 2017. Retrieved from https://www.cdc.gov/drugoverdose/pdf/PDO_Checklist-a.pdf
[64] Veterans Health Administration. (2000) Pain as the 5th Vital Sign Toolkit. Retrieved from https://www.healthquality.va.gov/guidelines/Pain/cot/
[65] World Health Organization, Guidelines for the psychosocially assisted pharmacological treatment of opioid dependence, 2009. (ISBN 978 92 4 154754 3). Retrived from http://www.who.int/substance_abuse/activities/treatment_opioid_dependence/en/
[66] Gaskin DJ, Richard P. (2012) The economic costs of pain in the United States. J Pain. Aug 2012;13(8):715–724.22607834
[67] AHRQ (2015), Implementing Medication-Assisted Treatment for Opioid Use Disorder in Rural Primary Care: Environmental Scan: Volume 2, Tools and Resources. https://integrationacademy.ahrq.gov/sites/default/files/MAT_for_OUD_Environmental_Scan_Volume_2.pdf
[74] Ezenwa MO, Suarez ML, . Implementing the PAINRelieveIt Randomized Controlled Trial in Hospice Care: Mechanisms for Success and Meeting PCORI Methodology Standards. West J Nurs Res. 2017 Jul; 39(7) 924–941. Web information at https://www.pcori.org/research-results/2013/computerized-painrelieveit-protocol-cancer-pain-control-hospice 27621272
[75] American Society of Anesthesiologists – Pain Medicine. (2014) Choosing Wisely. Retrieved from http://www.choosingwisely.org/clinician-lists/american-society-anesthesiologists-opioid-analgesics-as-long-term-therapy-for-non-cancer-pain/
[76] Cedars-Sinai. (ND) Patient Voinces in Chronic Pain. Retrieved from https://www.cedars-sinai.edu/Research/Research-Areas/CORE/Patient-Voices-in-Chronic-Pain.aspx
[77] Zedler, B., . (2015). “Development of a Risk Index for Serious Prescription Opioid-Induced Respiratory Depression or Overdose in Veterans’ Health Administration Patients.” Pain Med 16(8): 1566–1579.26077738
[78] Netherton, S. J., . (2014). “Computerized physician order entry and decision support improves ED analgesic ordering for renal colic.” Am J Emerg Med 32(9): 958–961.24997107
[79] Akce, M., . (2014). “A multifactorial intervention for hospital opioid management.” J Opioid Manag 10(5): 337–344.25350475
[80] Trafton, J., . (2010). “Evaluation of the acceptability and usability of a decision support system to encourage safe and effective use of opioid therapy for chronic, noncancer pain by primary care providers.” Pain Med 11(4): 575–585.20202142
[81] (J. Tripathi, personal communication, November 2, 2017)
[82] (K. Kawamato, personal communication, October 3, 2017)
[83] Caraballo, P. J., . (2015). “Clinical Decision Support to Implement CYP2D6 Drug-Gene Interaction.” Stud Health Technol Inform 216: 946.26262248
[84] Elfvengren K, Clinical Decision Support System for Opioid Substitution Therapy, IEEE HICSS Conference Proceedings 2015. http://ieeexplore.ieee.org/document/7070184/
[85] Clinical Decision Support for Opioid Use Disorders in Medical Settings: Pilot Usability Testing in an EMR (COMPUTE). (ND) Retrieved from https://www.drugabuse.gov/about-nida/organization/cctn/ctn/research-studies/clinical-decision-support-opioid-use-disorders-in-medical-settings-pilot-usability-testing-in-emr
[86] National Conference of State Legislatures. (ND) Prescription Drug Monitoring Programs. Retrieved from http://www.ncsl.org/research/health/prescription-drug-monitoring-programs-postcard.aspx
[87] The New Yorker Magazine. (2017) The Family That Built and Empire of Pain. Retrieved from https://www.newyorker.com/magazine/2017/10/30/the-family-that-built-an-empire-of-pain
[88] Losby JL, Hyatt JD, Kanter MH, Baldwin G, Matsuoka D. Safer and more appropriate opioid prescribing: a large healthcare system’s comprehensive approach. J Eval Clin Pract. 2017;1–7. 10.1111/jep.12756
[89] PROMIS (2017) Retrieved from http://www.healthmeasures.net/explore-measurement-systems/promis
[90] Northwestern Leads Consortioum to Integrate Patient-Reported Outcomes into Electron Health Records. (2016) Retrieved from http://www.healthmeasures.net/images/applications/EASIPRO_PressRelease_102016.pdf
[91] Labkoff, S., Bond, C., Kallenbach, L., Nguyen, N., Gangadhar, S., O’Brien, D. (2017) Reach and Impact of an HER Pain Care Clinical Decision Support Program. (Poster #82 at 2017 AMIA Conference)
[92] McNeely, Jennifer. (2017) Usability Testing to Guide Development of a Clinical Decision Support System for Substance Use Screening and Interventions in Primary Care. (2017 AMIA Conference presentation on November 8, 2017).