# 8 Conclusion

The opioid epidemic has expanded rapidly in the U.S.; attention and focus on management strategies is also expanding rapidly, although many of the guidelines and existing CDS are fairly recent and not widely implemented. A wide range of CDS artifacts applied at several points of the patient’s journey, for use by clinicians as well as patients, can and should be applied together to address pain management and opioid management concerns. Ideally, CDS that is recognizable to those who use CDS for other purposes would bring the quickest results: thus, familiar presentation types such as alerts, order sets, reminders, and smart data displays have an enhanced chance of acceptance and dissemination.

CDS Connect seeks to codify, standardize, and disseminate effective, usable, actionable CDS from a wide range of sources. Of the many guidelines and artifacts reviewed in this scan, the CDS Connect team will develop some and will also reach out to other CDS developers outside of the AHRQ and MITRE teams to edit and submit artifacts in the CDS Connect Repository. Together, these efforts should demonstrate and expand the capabilities of CDS Connect to house and disseminate a wide range of effective, shareable CDS for broad use by clinicians and patients.