# 7 Recommendations for CDS Connect

As the above discussion illustrates, there is early work on a fair range of CDS artifacts, segmented by: parts of the pain management and treatment journey, provider or patient focus, types of CDS presentation, integration with the EHR, and actionability of the result.

The AHRQ CDS Connect project has a 2017-18 task to identify, develop, and publish CDS artifacts in the pain management and prevention of opioid misuse arena. In identifying preferred CDS artifacts to produce, the following attributes are favorable to straightforward and effective completion of this task:

- The CPG, CQM, or clinical practice that the CDS will facilitate should be based on high-quality evidence and should have been developed by a well-respected governmental, provider, academic, or commercial source body without bias.
- The source content and/or clinical resources should be free of intellectual-property issues that could hamper or block open publication of the CDS artifact. Most guidance that is sourced from a U.S. government agency should be free of major IP issues; guidance from other sources needs review to ensure this will not be a problem.
- It is useful to extend the example space that CDS Connect handles by choosing artifacts that together represent more than one of the standard CDS presentation types (reactive alerts, reminders, order sets, tailored reference information, intelligent data displays, calculators, multi-patient displays, algorithms). The ability of CDS Connect to handle at least the first four or five of these options will be an important factor in its growth and acceptance within the community of CDS producers.
- At the same time, the amount of new effort needed to specify and develop these first new artifacts should be reasonable, so that the implementation can be successful in the contract time provided. More complex types such as longitudinal algorithms may be deferred to the next phase of CDS Connect development.
- If possible, the artifacts should be actionable and focused – giving specific recommendations that translate to actions or orders rather than simply providing an informational handout.
- The CDS artifacts chosen should cover varied parts of the problem space (e.g., one about dose reduction and one about treatment access).
- In keeping with the PCOR focus of CDS Connect, all artifacts should be patient-centered and one might potentially have patient-facing components. That said, patient-facing CDS is at a much earlier state of advancement than clinician-facing CDS in general, and the connection may not be directly to an EHR; thus, such an artifact specification also must include the description of the right vehicle that the patient can use to interact with it.
- If possible, the artifacts selected for development should not duplicate other efforts underway (particularly a known effort by CDC and ONC to convert opioid-related CDS to structured form). The use of CDC and other guidelines is still very reasonable.
- The artifacts should be chosen such that, in a pilot environment, they are likely to be invoked relatively frequently, and the data to support the logic should be readily available.

Based on the criteria outlined above, the MITRE team assembled a list of CDS artifacts for considered development. Deeper investigation into the technical feasibility of numerous options is indicated before a fully informed decision can be made. Potential development options are listed in Table 4, along with some of the benefits and constraints of each possibility.

Table 4 Potential CDS Artifact Development Options

(Higher numbers indicate greater degree of feasibility or impact.)

Type of CDS | Description and Trigger | Resource and/ or Data Dependency | Feasibility | Impact | Rationale
Alert | Check PDMP to determine total MME prior to signing an opioid order; Trigger: Opioid order | PDMP, MME, Med List | TBD | 5 | Benefit: If presented in an informative, user-friendly format this would facilitate workflow.; Constraint: States have distinct PDMP resources; therefore, code would need to be re-written to access another State’s PDMP system. In addition, the best approach to supporting PDMP data in CQL would be to use an “external” function definition, which means that the details of accessing the PDMP aren’t defined in the CQL but are left for individual implementation. This is a new feature in CQL 1.2 and is not yet implemented in the CDS Connect execution framework.
Reminder | Check PDMP every 3 months if receiving opioids.; Trigger: Follow up visit that evaluates time past and opioid order | PDMP, MME, Med List | 3 | 4 | Benefit: If presented in an informative, user-friendly format, this would facilitate workflow and prompt the reassessment of risk.; Constraint: To correctly evaluate “every 3 months,” the system would also need to record the last date the PDMP was checked (which is not captured in a structured way), or the date a medication was last ordered (which could prove challenging). If the reminder went on to link to the PDMP and display results, constraints listed above would be introduced.
Reminder/Order | Consider naloxone; Trigger: If on OT and >50 MME/day, concurrent use of benzodiazepines, or history of SUD | MME Calculator, Med List, Problem List | 3 | 5 | Benefit: Targets a preventive action; Constraint: May be deemed controversial by some provider or organizations. To support a trigger based on MME calculation, the CDS would also need to calculate MME (which is complex). Order sets provide additional constraints: FHIR Clinical Reasoning supports Order Sets, but not many vendors support FHIR Clinical Reasoning yet. This leads to subsequent considerations and the likelihood that an order set implementation would be proprietary to the pilot site.
Alert/ Order | Provide or recommend MAT for OUD; Trigger: New OUD diagnosis, a visit for an opioid-related crisis | Problem List, Encounter diagnosis, CPT | 5 | 4 | Benefit: Facilitates evidence-based treatment; Constraint: May be deemed controversial by some providers or organizations. May depend upon knowledge of local resources if patients need to be referred elsewhere to initiate MAT treatment. If presented as an order, the constraints listed above apply.
Order set | Opioid tapering guidance; Trigger: MME over a designated threshold | MME, Med List | 1 | 5 | Benefit: Would lessen opioid risk and reduce the need for providers to do the tapering calculation; Constraints: Very complicated to develop. Would require access to the MME result and the patient’s medication list, generating tapering guidance for a wide range of opioid dosages (and RxNorm codes). Technical constraints involving the specification of Order Sets apply.
Alert/Documentation Template | Pain assessment and follow up (PQRS 420); Trigger: Every encounter | Assessment, Care plan | 4 | 4 | Benefit: This is a PQRS measure, so IP approval should be reasonable. Numeric Rating Scale (NRS) alone would qualify. The measure will be part of MIPS, so valuable to providers.; Constraint: Will need to ensure the NRS isn’t copyrighted, ideally a functional status assessment is included also (which would need IP clearance). This does not address opioid prevention. FHIR’s standard CarePlan resource is not well supported by vendors. In addition, assessment/collection would likely happen via a Documentation Template (FHIR Questionnaire), which may not be supported by vendors. With standards potentially being out in front of implementation capabilities, a standard might be used to represent the concept, but the pilot implementation would be proprietary.
Flowsheet | Visualizes pain and functional assessment scores, medication start and stop date, dosage, total MME, and additional therapies; Trigger: Encounter when pain “diagnosis” and active pain medication are present | MME, Med List/Order, Problem List | 2 | 4 | Benefit: Enables provider and patient to establish appropriate prescription of buprenorphine for opioid use disorder (OUD) [34], and treatment effectiveness and correlations between treatment and the patient’s experience, aiding shared decision making; Constraint: Requires additional research from a technical perspective. Scores are likely not captured in a structured format.
Alert | Consider non-opioid medication; Trigger: opioid order (if no evidence of non-opioid med in last 3 months) | Med List | 5 | 4 | Benefit: May facilitate opioid avoidance; Constraint: May disrupt workflow if the provider has already considered this treatment and discussed the risks, benefits, and options. Might also be presented as an order set with various suggestions for treating mild, moderate, severe pain, but technical order constraints would apply.
Reminder/Order | Order follow-up appointment within 3 months for patients on long-term OT; Trigger: Active opioid medication for > 3 months | Med List, Encounter data | 4 | 3 | Benefit: Facilitates reassessment of risk and benefit.; Constraint: Very challenging to decipher “time passed” from captured EHR data. Unable to schedule an appointment via an action by the provider. Negative impact on workflow may outweigh the clinical advantage.
Reminder | Consider adding non-pharmacologic therapies when a pain medication is ordered (opioid or non-opioid); Trigger: Opioid order with the presence of a pain diagnosis | Problem List, Med List | 2 | 4 | Benefit: Follows evidence-based recommendations, may lessen the need for pain meds; Constraints: Many non-pharmacologic therapies are defined by SNOMED-CT codes, which are not implemented in many EHRs. If this intersects with the order (i.e., recommends adjusting the order to include a non-pharmacologic therapy), the technical requirements become very challenging.