# 6 Identified Pain Management CDS Efforts

As noted in previous sections, many steps in the pain management patient journey have best practices that lend themselves to CDS, directed to providers, patients, family, social entities and quality leaders. This is a relatively new area for CDS, however, compared to well-established targets such as adverse drug events and health maintenance. As a result, the number of developed and implemented CDS artifacts is relatively small. Also, current CDS generally follows patterns that applied to these earlier targets, such as dose alerts and information advisories. Here we review identified CDS efforts, categorized by the care objective that each effort supports.

## 6.1 Patient-Centered Pain Assessment

Pain assessment lends itself to patient use, either alone or in collaboration with a clinician. Smart entry forms with pain score calculations built in, interactive reference for patients, and care plans or order sets for clinicians can all be useful in both collecting data and making data-driven decisions. The Veteran Health Administration’s (VHAs) Clinical Pain Reminders include a wide range of smart documentation forms geared towards nurses and providers related to pain assessment and reevaluation, in a wide range of situations including chronic pain and post-procedure pain.

PainCAS [33], a for-profit, patient-facing tool created through initial funding from NIH, provides patient reminders to complete opioid-risk assessments, either at home via a patient portal or in a clinician’s waiting room on a tablet. The CDS evaluates the answers and scores the assessment, giving the provider concise information to support decision-making.

Despite being created to facilitate pain care for cancer patients in hospice care, the CDS tools created by the PAINRelieveIt (https://www.pcori.org/research-results/2013/computerized-painrelieveit-protocol-cancer-pain-control-hospice) study funded by PCORI may provide valuable resources to promote patient-centered assessment of nonmalignant pain care. The study implemented CDS logic delivered via a tablet-based assessment tool that generated a report and analgesic recommendations to hospice nurses, along with multimedia education tailored to patients and their lay caregivers [74].

Research efforts presented at the 2017 American Medical Informatics Association (AMIA) conference provide additional insight as to how CDS can facilitate patient-centered assessments. Purdue Pharma found alerts successful in improving the administration of multidimensional assessments and documentation of the results to better manage pain care [91], and a NIDA-sponsored study found that EHR modifications were required to achieve adequate usability of CDS to deliver optimally-timed alerts to providers with assessment scores and risk stratifications [92]. The NIDA research also provides insight to identifying at-risk patients.

## 6.2 Opioid Avoidance

Opioid avoidance CDS could include order sets for pain syndromes (back pain is especially common) to steer a provider to alternative therapies, including complementary medicine and non-opioid analgesics. This could also be realized as alerts that trigger when an opioid prescription is entered.

The Choosing Wisely [75] program contains several opioid-avoidance artifacts. The American Society of Anesthesiologists Choosing Wisely recommends avoiding the prescription of long-term opioids for non-cancer pain unless risks are considered and discussed with the patient. While this is a guideline and not CDS, companies such as Stanson have taken large parts of the Choosing Wisely set and implemented them in a form permitting easy upload into Epic and other EHRs. Thus, reusable CDS is being applied to opioid avoidance with some success.

Another interesting effort from Cedars-Sinai, Patient Voices in Chronic Pain [76], provides alerts and reminders upon each new prescription of refill of long-acting opioids, recommending avoidance when possible; provides alerts for concomitant prescribing of opioids and benzodiazepines, which can cause magnified sedative effects; and also runs analyses to identify patients at risk of opioid-related harms. The Cedars-Sinai work also provided patient education and activation tools (PEATs) via the patient portal prior to office visits to facilitate shared decision making during the visit [76]. PEATs, whether triggered by the presence of opioids on the medication list (which qualifies as CDS) or manually invoked, are valuable resources that can reinforce effective alternatives to opioids, including self-management, complementary therapies, and nonopioid medications.

Overall, there are a few efforts in this area, primarily alerts that are triggered by an opioid prescription and try to show both elevated risk profiles and alternative options. Further efforts could be devoted toward more proactive CDS, such as order sets, which can be targeted to a given problem (back pain, sickle cell pain, etc.) and which are better accepted than alerts. Regardless of CDS type, there appears to be more room for increased awareness and facilitation of complementary therapy ordering.

## 6.3 Identifying At-Risk Individuals

This category includes displays, particularly PDMP displays, but also monitoring other determinants of health to ideally calculate and show at a glance whether a patient is at low, medium, or high risk of excessive opioid use and addiction. The category also could include monitoring algorithms that check a patient’s ongoing use of prescribed opioids, and intervene to recommend dose reduction after a period of time.

Several interesting efforts look for determinants within the EHR. The University of Florida Collaborative Health Outcomes Information Registry (CHOIR) project identifies patients with more than a few chronic pain codes in their EHR. With this information it can decide, when a new patient arrives for a visit, to alert administrators to offer high-risk patients a CHOIR (registry) survey. This prompt can bring more patients into treatment, compared to more passive means.

The VHA [77] has developed risk score calculators assessing the risk of overdose or serious opioid-induced respiratory depression (RIOSORD) based on 15 variables including drugs used, mental health disorders, pulmonary disorders, and recent hospitalization. This was prototyped by VHA and has been used, tested, and commercialized by Venebio [61]. The commercial software can administer surveys to patients as they wait in the waiting room of the practice; then, by combining the patient’s responses with EHR data, the software can provide an overall risk assessment and make the information available to the clinician.

Alert or dashboard formats make sense for identifying patients at risk. Future work could further refine the algorithms, which now heavily depend on PDMPs, to incorporate social determinants of health.

## 6.4 Dose Reduction

Much of the existing opioid-related CDS is directed toward prescribing, including dose-reduction order sets and alerts that assess total MME dosing. As noted above, these are fairly easy to create and easy for users to understand and accept, since they are familiar with similar CDS encountered during their regular drug prescribing.

The range of demonstrated dose-reduction CDS includes simple MME displays and smarter calculators based on a patient’s complete medication list; alerts for excessive daily MMEs or total prescription amounts; order sets targeted to a particular problem (such as lower back pain) that guide dosing while also promoting non-opioid therapies; and surveillance analytics that can run periodically to find patients with worrisome prescription fill and usage patterns. Order sets have also been used to both reduce morphine dosing and direct prescribers toward non-opioid medications, such as ketorolac for renal colic [78].

In keeping with CDS principles that call for multifaceted CDS at different parts of the workflow, some organizations have tried combination CDS, including order sets to reduce ordering and pain management information displays [79]. Multi-panel smart data displays (dashboards), another form of CDS, can give comprehensive information about a patient’s current opioid prescription load, display guidance specific to the patient’s pain syndrome, and present a checklist for opioid management actions [80]. A current research effort at MITRE combines a PDMP display and past-prescription history to determine patients who are at or over the top of recommended prescribing maxima [81].

Kaiser Permanente of Southern California completed a 5-year multi-pronged set of interventions including CDS to alert for large daily doses, large total prescribed amounts, and combined prescribing of opioids with benzodiazepines [88]. Outcomes from the organization-wide effort demonstrated the overwhelming impact that policy, provider training, and CDS can have on prescribing practices: 30% reduction in prescribing opioids at high doses; a 98% reduction in the number of prescriptions with quantities greater than 200 pills; a 90% decrease in the combination of an opioid prescription with benzodiazepines and carisoprodol; a 72% reduction in the prescribing of Long Acting/Extended Release opioids; and a 95% reduction in prescriptions of brand name opioid-acetaminophen products [88].

A welcome technological advance is the use of more interoperable CDS technologies. Implementations of selected CDS from the CDC guideline set have been realized in Clinical Quality Language (CQL), using Fast Healthcare Interoperability Resources (FHIR) profiles [12] and CDS Hooks [82]. The use of these technologies facilitates sharing the CDS across multiple sites with different EHR technologies and data dictionaries, consistent with the philosophy underlying the CDS Connect repository.

Genomic opioid prescribing decision support is also appearing. As noted previously, the Mayo Clinic has CDS to detect the CYP2D6 drug-gene interaction [83]. The next step would be to use this information to drive different dosing levels for the same problem in different patients, just as dosing reduction software has been implemented for renal failure patients.

## 6.5 Opioid Use Disorder Treatment

There is not much published at this time about live CDS that facilitates OUD treatment. This is a significant gap area, as CDS could be valuable for identifying patients in need of prompt treatment, monitoring response to outpatient treatment that is tailored to each patient, and facilitating the access to and prescribing of buprenorphine and other MAT drugs. These could be presented as order sets, flowcharts following treatment with alerts, and alerts from payer-contracted monitoring programs, such as those which periodically contact patients with chronic obstructive pulmonary disease (COPD) or atrial fibrillation.

Elfvengren [84] has developed a set of tools to facilitate the various processes of chronic, nonmalignant pain management. These are mainly presented as static forms that are available at appropriate points. However, these certainly do qualify as CDS, as they are data-driven, only appear for appropriate patients, and bring information reminders at strategic points in care.

Another early NIH-supported project at the University of Minnesota [85] is evaluating CDS targeted at OUD treatment, including guidance and facilitation of buprenorphine prescribing.

As with many of these newer efforts, it will be important to see the impact of this CDS on care processes and outcomes.