# 5 Identified Pain Management Resources

The environmental scan led to the identification of a very large number of clinical resources to inform and facilitate chronic, nonmalignant pain management. The research team considered two approaches to categorizing the items that were most likely to contribute to a CDS artifact:

1. By what segment of care the item supported (i.e., patient-centered pain assessment, opioid avoidance, identification of at-risk individuals, opioid reduction, opioid dose reduction, and the treatment of opioid use disorder)
2. By what type of CDS artifact the item would facilitate (e.g., an order set, checklist, alert), since the CDS Connect team aims to develop diverse types of CDS to support pain care

The team opted to categorize and present scan findings based on the former (the care process that items support), since this approach provides the most contextual understanding of the resource. The “type of CDS” that a resource might lend itself to will be one of several factors considered during discussions on what content to develop.

The sections below include a representative sample of resources that might inform, augment, or facilitate patient-centered CDS artifacts to support pain care and the proper prescription of opioids. Resources discussed in this section are intended to highlight how the identified item might contribute to a patient-centered artifact. The Pain Management Environmental Scan Catalog includes a broader list of resources identified during the scan. Although not listed specifically, the MITRE team is aware that pain treatment, resources, and recommendations can vary slightly based on the underlying etiology of the pain (e.g., rheumatoid arthritis, migraines). Addressing each unique etiology will likely be outside the scope of CDS Connect artifact development efforts.

## 5.1 Patient-Centered Pain Assessment

Pain as a symptom is multifaceted and influenced by a range of physical, psychosocial, and behavioral factors [3]. As a result, measuring pain intensity alone offers little insight into the quality or character of an individual’s pain experience [49]. A comprehensive pain assessment includes a biopsychosocial interview and focused physical exam [9]. Elements of the biopsychosocial pain interview include a pain-related history; assessment of pertinent medical and psychiatric comorbidities, including personal and family history of SUD, functional status, and functional goals; coping strategies; and a variety of psychosocial factors, such as the patient’s beliefs and expectations about chronic pain and its treatment [50].

Dozens of clinical resources are available to support pain assessment and diagnosis. They include, but are not limited to:

- Pain Intensity Ratings: Numeric Rating Scale (NRS), Verbal Rating Scale (VRS), Facial Iowa Pain Thermometer
- Multidimensional Assessments: Pain, Enjoyment, and General Activity (PEG), Brief Pain Inventory (BPI), Defense Veteran Pain Rating Scale (DVPRS)
- Anxiety and Depression Assessments: Patient Health Questionnaire (PHQ)-4, PHQ-9, General Anxiety Disorder (GAD)-7
- Functional and Other Assessments: Health Status Questionnaire (SF)-36, Quality of Life (QoL) Survey

Many of these surveys and questionnaires can be self-administered, provided they are scored and interpreted by a health care professional. Tools that assist in shifting focus beyond pain intensity alone are valuable resources to evaluate treatment response, functional status, patient well-being and quality of life [51]. Assessment responses can be used to inform diagnosis, the plan of care, and the effectiveness of the care during subsequent patient visits.

Clinical practice guidelines from organizations such as the VA/DoD and the Institute for Clinical Systems Improvement encourage the use of multidimensional assessments to evaluate and diagnose pain. These assessments are prime candidates for patient-centered CDS artifacts since they engage patients, encourage the expression of their pain experience, and become a foundation for shared decision making as a plan of care is established.

## 5.2 Opioid Avoidance

Education is vital for patients with chronic pain. The goal of chronic pain management is to safely and effectively reduce pain and improve function and quality of life [13]. Complete eradication of chronic pain is an unrealistic expectation and should not be a goal for the patient or the medical provider [9]. Many providers and patients are still coming to terms with this shift in paradigm. Resources are available to both patients (e.g., PainACTION (http://painaction.wpengine.com/wp-content/uploads/2017/08/Your-Guide-to-Pain-Management.pdf), Which Treatment is Right for You? (https://www.consumerreports.org/pain-relief/pain-management-treatment-right-for-you/)) [52,53] and providers via continuing education, training modules, and internet resources (e.g. PainEDU, Nonopioid Treatments for Chronic Pain (https://www.cdc.gov/drugoverdose/pdf/nonopioid_treatments-a.pdf)) [54,55] to assist with buy in and adherence with this approach,.

CDC and VA/DoD CPGs recommend against initiation of long-term opioid therapy for chronic nonmalignant pain [9,10] and state that non-pharmacologic therapy and non-opioid pharmacologic therapy are the preferred methods of treatment [9,10]. Examples of non-pharmacologic therapies include:

- Self-management skills, which may address stretching and exercise, the use of spa, relaxation skills, pacing, record-keeping (diary), weight loss, medication management, yoga, tai-chi, or bibliotherapy.
- Cognitive Behavioral Therapy (CBT) and Behavioral Activation and Acceptance and Commitment Therapy (ACT) are therapies that also show promise. Psychological treatments may be delivered in individual or group formats.
- Relaxation techniques.
- Physical therapy (which also includes coaching and development of exercise/activity programs).
- Identification and treatment of comorbid conditions, in particular depression, substance use disorder, and insomnia [56].

No matter what form of treatment is initiated, patient education is integral. If and when medications are indicated, providers are encouraged to first consider non-opioid analgesics such as acetaminophen, nonsteroidal anti-inflammatory drugs (including COX-2 inhibitors), ibuprofen, and aspirin [3]. “Adjuvant analgesic drugs” often used for other conditions can also be considered (e.g., anticonvulsants or psychotropic classes) [3].

When prescribed, opioid medications should never be the sole therapy [13]. Multi-modal treatment therapies addressing the biopsychosocial-spiritual needs of the patient (as above) should be employed as safe best practices [13]. Detailed opioid prescribing guidance is provided in numerous CPGs [9,10,42–44].

## 5.3 Identification of At-Risk Individuals

Prior to initiating opioid therapy, it is imperative to closely scrutinize an individual’s risk of misusing the medication (i.e., using the opioid in a way that is not medically sanctioned, such as dose escalation, bingeing on opioids, or crushing controlled-release tablets) [57]. Clinical practice guidelines urge providers to perform a baseline risk assessment to evaluate the feasibility of prescribing an opioid, and periodic assessments while a patient is receiving opioid therapy [9,10].

Providers can assess the risk of opioid misuse in numerous ways:

- Determining risk by predisposition: identifying patients with chronic pain International Classification of Diseases (ICD) codes, existing sedative or narcotic prescriptions (while also evaluating the total MME exposure and how long the patient has been receiving opioids), a history of substance abuse, depression, anxiety, and even arthritis [58].
- Determining risk by demographics: 18-25 years of age, rural setting, education level, low socioeconomic status, employment status, disability status, history of criminal behavior [59].
- Determining risk by clinical features: withdrawal symptoms, escalating reports of pain despite stable chronic condition.
- Utilizing patient-facing tools: opioid risk assessments such as Screener and Opioid Assessment for Patients with Pain (SOAPP-R), Opioid Risk Tool (ORT), and Current Opioid Misuse Measure (COMM), and many more.
- Utilizing provider-facing tools: PDMP, UDT, and Automation of Reports and Consolidated Orders System (ARCOS).
- Utilizing predictive analytics: The High-Risk Dashboard [60] and proprietary products like the Venebio Opioid Advisor which calculates risk based on demographic and clinical variables [61].

VA/DoD clinical practice guidelines suggest mitigating risk via periodic UDT and PDMP checks, face-to-face follow up encounters (with frequency determined by risk), overdose education, informed consent, providing alternative therapies, and naloxone distribution [3]. CDS artifacts that facilitate these risk mitigation techniques will provide a valuable means to maintain patient safety.

## 5.4 Opioid Dose Reduction

Many resources are directed at reducing opioid exposure in prescriptions: reducing the prescription of opioids and benzodiazepines, reducing the daily dose, reducing total amount dispensed, reducing opioid dose at refill time, or eliminating refills altogether. This has been a natural focus for CDS as well as guidelines, since it is squarely part of the prescribing workflow, where CDS has long had an accepted role. Tools and resources, as well as CDS, are dedicated toward ensuring that prescribers understand the MME of different drugs, helping them stay under guideline-driven limits, and providing recommendations for ongoing monitoring to reduce dosage as soon as possible. CDC has produced a mobile app with dosing guidance and MME calculators [62]. Other resources range from checklists [63] to information pages describing opioid effects to patient agreements that reinforce the seriousness of opioid prescribing. More interactive tools are described in Section 6.

The VA/DoD Clinical Practice Guideline for Opioid Therapy for Chronic Pain contains four bundled modules and algorithms for determining if opioid therapy (OT) is appropriate, and how to implement, monitor and taper OT [9]. Each module includes a detailed flowchart. The CPG also provides a documentation form that allows a provider to record the condition, social factors, treatment, results, and effects, which can be very valuable in determining the minimum dose that is effective for pain control [9].

A newer addition has been the inclusion of genomics in opioid prescribing, particularly targeting variations in the CYP2D6 gene, which dictates the effectiveness and toxicity of codeine-family drugs. Identifying very high or very low metabolizers can prevent toxic events and excessive dosing [44]. Additionally, there have been a small number of patient-facing dose reduction tools, such as PainCAS (mentioned previously), which provides prescribing guidance based on assessed opioid risk [33].

It is worth noting that, until recently, there was a significant push to prioritize sufficient pain control and to avoid inadequate dosing of analgesics (e.g., the “Pain is the 5th Vital Sign” campaign [64] and others); this likely had the effect of increasing such processes as routine post-procedure opioid prescriptions. With the more recent intense focus on the opioid epidemic, guidance and CDS have had to reverse some of the stronger statements of the previous campaign and misinformation directed at physicians [87].

## 5.5 Opioid Use Disorder Treatment

There has been considerable evolution and discussion about access to treatment and treatment methods for patients who are actively using opioids in an addictive pattern. Whether active OUD began with prescription drugs or illicit drugs, evidence increasingly shows that active users with OUD need prompt and sustained treatment to return to sustained non-use [65]. OUD treatment must commence promptly after significant events such as overdoses or a change in social environment (e.g., release from incarceration), and the duration of treatment should be tailored to each individual patient [65]. While both abstinence therapy and medication-assisted therapy (MAT) have advocates, there is increasing support for MAT as a mainstay of treatment, along with behavioral support [66].

OUD treatment resources focus on several areas:

- Provider selection of and management of MAT therapy, using the various drugs available
- Education for patients and family caregivers about MAT drugs and their effects;
- Monitoring templates for following both side effects and response to therapy (both MAT and psychosocial)

Both ASAM and VA/DoD authored 2015 practice guidelines that can educate professionals about the selection of MAT as well as its use with psychosocial addiction therapies [45,46]. AHRQ recently commissioned an environmental scan focused on MAT for OUD in rural primary care [67], which contains a variety of guidelines and educational resources.