# 4 Chronic Nonmalignant Pain Management

In the wake of the opioid crisis, the treatment of chronic, nonmalignant pain has become much more controversial. It is well documented that the sales of prescription opioids have quadrupled since 1999 [20]. This was the result of physicians from across the country being subjected to a multi-million-dollar marketing campaign from the pharmaceutical industry over several years [21]. As an example, this campaign brought us the concept of “pain as a fifth vital sign” [22]. As fatal opioid overdose rates continued to climb, the medical community recognized that treating pain was a very complex issue [22]. In March 2016, the Centers for Disease Control and Prevention (CDC) published guidelines for prescribing opioids for chronic pain, which helped to bring some clarity to this topic [23].

CDC guidelines encourage prescribers to consider nonpharmacologic therapy and nonopioid pharmacologic therapy when treating chronic pain (i.e., pain lasting > 3 months or past the time of normal tissue healing), measure goals for pain and function [10], and encourage self-management. As Fitzcharles and Shir state: “Pain treatment should take into account symptoms that co-associate with pain, and proceed in parallel with the best management of the underlying rheumatologic process. Outcome for any treatment should not only be measured as pain relief, but also as an improvement in function” [24]. Additional approaches to chronic pain include:

- Identify and address co-existing mental health conditions (e.g., depression, anxiety).
- Use disease-specific treatments when available.
- Use first-line medication options preferentially.
- Consider interventional therapies (e.g., corticosteroid injections) when non-invasive therapies fail.
- Use multimodal approaches for select individuals [25].

Nonpharmacologic pain management methods, often the first line of treatment, can be divided into three categories: physical techniques (such as manipulation and exercise), psychological techniques (such as cognitive behavioral therapy, hypnosis, and relaxation/meditation), and social/environmental interventions (such as community support groups and work changes) [26].

- Physical techniques: These techniques include exercise and activities, manual therapies (e.g., manipulation, mobilization, and massage), and hyperstimulation analgesia (e.g., acupuncture, transcutaneous electrical nerve stimulation, and ice massage). The goal of physical techniques is to reduce the severity of the pain so that the patient can resume normal activities. Therefore, these techniques are more effective for acute pain states, and less achievable for persisting pain [26].
- Psychological techniques: All pain management treatment requires some level of psychological technique (e.g., active listening, providing advice, assurance, and encouragement, education/information provision). However, some patients can benefit from additional psychological techniques such as cognitive behavioral therapies, relaxation techniques, biofeedback, attentional techniques, meditation, hypnosis, and psychotherapy. Psychological techniques can be used as the primary treatment, but most commonly they are used as a facilitating technique. Careful assessment should be made to determine the most effective approach [26].
- Social/Environmental techniques: If environmental factors are a contributing factor in the persisting pain of the patient, then corresponding changes in the patient’s environment may be in order (e.g., in the workplace) [26].

If nonpharmacologic and nonopioid therapies (e.g., ibuprofen, acetaminophen) fail to treat pain and improve function adequately, guidelines developed by the CDC, Department of Veterans Affairs/Department of Defense (VA/DoD), and other highly regarded institutions list a series of steps for providers to follow when considering long-term opioid therapy (e.g., assess baseline pain and function, patient goals and preferences, discuss benefits and risks, check prescription drug monitoring program (PDMP) and urine drug test (UDT) data to evaluate the risk of opioid misuse, reassess within 1- 4 weeks of opioid initiation, and prescribe short-acting opioids using the lowest dosage on product labeling [9,10]). Basing care decisions on these evidence-based recommendations, while ensuring patient-centered, patient-specific care will enhance the likelihood of a successful pain management regimen.

## 4.1 Patient-Centered Pain Management

Success in addressing the opioid crisis and evidence-based pain management requires a multifactorial, multidisciplinary, patient-centered approach to prevention and treatment. Additionally, it involves an actively engaged, willing patient. These two factors are intricately interwoven.

A patient-centered care (PCC) approach is identified by The Institute of Medicine (IOM), in Crossing the Quality Chasm: A New Health Care System for the 21^st^ Century (2001) as one of the major aims for all health care organizations and is reflected in six dimensions (listed in Table 2 below).

Table 2 Six Dimensions of Patient-Centered Care [27]

Six Dimensions of Patient-Centered Care
1. Respect for patients’ values, preferences, and expressed needs; 2. Coordination and integration of care; 3. Information, communication, and education; 4. Physical comfort; 5. Emotional support-relieving fear and anxiety; 6. Involvement of family and friends

The report describes patient-centeredness as encompassing the qualities of compassion, empathy, and responsiveness to the needs, values, and expressed preferences of the individual patient. It is individualized care based on aspects such as a patient’s capabilities, needs, goals, motivation, and preferences; applies a biopsychosocial perspective (including addressing social determinants of health) rather than a purely biomedical perspective; and forges a strong partnership between patient and clinician.

Effective PCC has demonstrated improved adherence, improved outcomes [28], satisfaction, self-management [29], and reduction of diagnostic tests and referrals [30]. Increased focus on PCC and its effectiveness in impacting cost, quality, access, and satisfaction is reflected in the recent Request for Information from the CMS Innovation Center’s New Direction [31] for feedback on a new direction to promote patient-centered care and test market-driven reforms.

The focal areas and attributes of a patient-centered health care system (expanding the IOM six dimensions of PCC) are provided in Table 3 (below). Foundational in achieving these dimensions is a trusting relationship with the patient, family, and health care team, enabled by open and honest communication with active listening, information sharing, joint decision making with realistic goals, and joint accountabilities. Bottom line: The goal of patient-centeredness is to customize care to the specific needs and circumstances of the individual [27].

Key aspects to pain management include: understanding the patient’s perception of pain through pain and biopsychosocial assessment tools, the impact of the pain on their well-being and quality of life, their perception of non-pharmacologic modalities of pain treatment, and their goals.

Table 3 Dimensions and Attributes of a Patient-centered Health Care System [32]

Interpersonal; (Relationship) | Clinical; (Provision of Care) | Structural; (System Features)
Communication; - Begins with listening; - Creates a fabric of trust; - Promotes clear, empathic communication, tailored to patients’ needs and abilities; - Welcomes participation of family, friends, and caregivers | Clinical Decision Support; - Ensures shared decision making based on best-available evidence coupled with patient preferences; - Supports self-management | Build Environment; - Provides calm, welcoming space; - Accommodates patient, clinician, and family needs; - Emphasizes easy “way-finding” and navigation through the system
Knowing the Patient; - Uses knowledge of the patient as a whole and unique person for effective interactions; - Finds common ground based on patient preferences; - Facilitates healing relationships | Coordination and Continuity; - Manages care transitions and seamless flow of information, whether for a broken arm or life-altering illness; - Coordinates with community resources | Access to Care; - Eases appointment-keeping process; - Minimizes clinic wait times; - Payment system accommodates patients’ circumstances; - Coordinated, consistent, efficient
Importance of Teams; - Ensures responsiveness by entire care team to patient and family needs; - Recognizes that actions of both clinicians and staff can influence perceptions of care | Types of Encounters; - Accommodates virtual visits (phone, email) as well as in-office visits; - Reimbursement structure supports range of encounters that meet patients’ varied needs | Information Technology; - Supports patient and clinician before, during, and after encounters; - Tracks patients’ preferences, values, and needs dynamically; - Provides self-management tools and information

The EHR, patient portals, and CDS resources (such as automated pain assessment tools like PainCAS [33]) are fundamental in facilitating PCC. Several patient-centered research efforts are underway to facilitate pain management and opioid prescribing via CDS, including the use of alerts to survey patients about the outcome of their pain treatment [35], provide prescribing guidance, identify high-risk patients for opioid-related harms, and provide patient education and activation tools via a patient portal [36].

## 4.2 Pain Management Clinical Resources

Professional organizations, government agencies, non-profit organizations, prominent scientists, academic institutions, and others have developed a vast and varied amount of clinical resources to inform and guide clinicians as they deliver patient care. Resources include (but are not limited to) clinical practice guidelines, clinical quality measures, assessments, calculators, care plans, and flow sheets. Consequently, CDS developers utilize these resources to inspire and support the CDS specifications.

### 4.2.1 Clinical Practice Guidelines

The National Guideline Clearinghouse, managed by AHRQ, houses a wealth of guidelines that focus on chronic pain management and opioid prescriptions (i.e., a search of “chronic pain” returned 72 guidelines, and “opioid” returned 152). The MITRE team reduced the queried sample further by eliminating topics outside the scope of the project (e.g., cancer pain, acute pain, radiology guidance), leading to a deeper dive of approximately 12 CPGs. The team noted significant overlap of guidance regarding treatment principles in the most recent releases of many of the guidelines.

Prior to publishing the CDC Guideline for Prescribing Opioids for Chronic Pain in 2016, the CDC’s National Center for Injury Prevention and Control, National Institute on Drug Abuse (NIDA), Substance Abuse and Mental Health Services Administration (SAMHSA), and the Office of the National Coordinator for Health Information Technology (ONC) conducted a systematic review of eight evidence-based guidelines. The joint effort identified the following commonalities across guidelines:

- Conduct a physical exam, pain history, past medical history, and family/social history.
- Conduct urine drug testing, when appropriate.
- Consider all treatment options, weighing benefits and risks of opioid therapy, and using opioids when alternative treatments are ineffective.
- Start patients on the lowest effective dose.
- Implement pain treatment agreements.
- Monitor pain and treatment progress with documentation, using greater vigilance at high doses.
- Use safe and effective methods for discontinuing opioids (e.g., tapering, making appropriate referrals to medication-assisted treatment, substance use specialists, or other services) [37].

Though not listed in the commonalities, the reviewers also felt that the use of data from PDMPs to identify past and present opioid prescriptions at initial assessment and during the monitoring phase would become an integral part of opioid prescribing as States enhanced their monitoring technology [37]. As of 2016, at least 26 States and Guam required prescribers to use the PDMP before writing opioid prescriptions [86]. As MITRE researchers delve further in to determining which evidence-based recommendation(s) to specify as CDS, guidance that aligns with 1) the above themes, and 2) IOM-outlined criteria for trustworthy guidelines (e.g., generated after a systematic review, include ratings for the strength of evidence and recommendations) [38] will be favorably considered.

Evidence-based guidelines identified as high-value “source” content from which a CDS artifact might be derived, were published within the past 5 years and provide guidance on pain management [40,41], opioid prescribing [9,10,42–44], and opioid use disorder treatment [45,46]. With AHRQ sponsor and CDS Connect Work Group input, the MITRE team will identify recommendation statements within one or more of the CPGs to serve as the foundation for CDS artifacts. Given lessons learned during the initial period of performance of the CDS Connect project, gaining intellectual property approval from government entities that have authored CPGs may be more feasible and timely than seeking permissions from professional organizations.

### 4.2.2 Clinical Quality Measures

Clinical quality measures evaluate the degree of compliance with the clinical practice guideline (or standard of care) that a CQM is based upon. CQMs, and in particular eCQMs, serve as excellent starting points for CDS because the logic, data elements, exclusions, exceptions, and value sets representing each data concept are specified. As a result, there is little room for misinterpretation. Furthermore, National Quality Forum (NQF)-endorsed eCQMs have demonstrated the accuracy, feasibility, reliability, and validity of measure logic and data elements utilized in the measure. Basing a CDS artifact on endorsed e-specifications provides reasonable assurance that the data evaluated by CDS logic will be accurate and routinely available in a structured format.

Unfortunately, United States Health Information Knowledgebase (USHIK) and the National Quality Measures Clearinghouse (NQMC) house only one eCQM related to nonmalignant pain: CMS 166v6 Use of Imaging Studies for Low Back Pain, which is outside the scope of project efforts. A search in VSAC identified three organizations that may be working toward e-specification of pain or opioid-related resources: SAMHSA, ECRI Institute, and American Academy of Neurology (AAN). The value sets created by these organizations are not tied to specific eCQMs at present, although AAN is the author of a Physician Quality Reporting System (PQRS) measure (i.e., PQRS 414: Evaluation or Interview for Risk of Opioid Misuse), which does include some terminology specifications (e.g., a list of Current Procedural Terminology [CPT] codes for encounters).

The research team identified numerous organizations that have authored text-based CQMs in our area of interest; several published entire suites of CQMs in the pain management [68–70] and opioid [71,72] domains. However, most of these measures lack distinct details that would readily support e-specification, rendering them less informative to project efforts. The CMS Measure Under Development list includes an AHRQ measure titled, “Pain Assessment for Chronic Pain,” which bears additional investigation.

The team did pinpoint four new measures that appear instructive, due to the level of detail that is provided in the published manuscripts. Although the measures are not e-specified, they do list some standardized codes for certain concepts.

- Use of Opioids from Multiple Providers (UOP) – a 2018 Healthcare Effectiveness Data and Information Set (HEDIS) measure based on administrative data [73]
- Use of Opioids at High Dosage (UOD) – a 2018 HEDIS measure based on administrative data [73]
- PQRS 0420: Pain Assessment and Follow Up – a CMS measure that will be used in the 2018 Merit-based Incentive Payment System (MIPS) [47]
- PQRS 414: Evaluation or Interview for Risk of Opioid Misuse – a 2017 and 2018 MIPS measure [47]

In 2014, a panel within American Society of Addiction Medicine’s (ASAM) Practice Improvement and Performance Measurement Action Group identified the following barriers to implementation of CQMs and eCQMs in the addiction domain:

- Identifying the presence of a treatment plan in the EHR in a standard, structured way
- Assessing treatment duration
- Tracking referrals
- Determining attendance or utilization frequency of psychosocial interventions (since they often occur off-site and are not documented in the EHR)
- Reconciling data systems between medical and behavioral health systems
- Lack of specificity for psychosocial treatments for addiction codes (e.g., CPT codes)
- Lack of CPT-specific codes for certain types of addiction (e.g., outpatient withdrawal management for OUD, buprenorphine induction and medication transitions like methadone to naltrexone or methadone to buprenorphine) [48]

Given the panel’s findings, the absence of eCQMs in the addiction domain at this time is not surprising. The MITRE team plans to exercise caution as CDS artifacts are considered for development, given these identified constraints.

#### 4.2.2.1 PROMIS® Measures

Patient-Reported Outcomes Measurement Information System (PROMIS) is a set of person-centered measures developed with National Institutes of Health (NIH) funding to evaluate and monitor physical, mental, and social health in adults and children to support research assessment and clinical care [89]. The measures are relevant across all conditions to assess symptoms and functions, including pain intensity and interference [89].

In October 2016, NIH awarded Northwestern and a consortium of nine universities a $6.3 million grant to accelerate the use of patient-reported outcomes by integrating the PROMIS measures into EHR systems [90]. Efforts are underway to integrate the measures in Cerner and Epic, two of the largest vendors [90]. Use of the measures to inform clinical care will likely increase once the questions and responses are integrated in the EHR.

Based on information gleaned during MITRE research, CPGs appear to mention the use of multidimensional assessments (e.g., Pain, Enjoyment, and General Activity [PEG]) to inform pain management, as opposed to PROMIS assessments. Additional investigation is required to determine if and how select PROMIS questions intersect with questions included in the multidimensional assessments mentioned in CPGs and other literature.

### 4.2.3 Clinical Tools

Dozens of tools are available to clinicians, social workers, counselors, and patients to manage care provided to a patient experiencing pain. These resources include recommendation statements, educational materials (for patients and providers), pain assessment questionnaires, opioid misuse risk assessments, care plans, flowsheets, protocols, and checklists, to name a few.

Tools identified during the scan that might contribute to a CDS artifact in the pain management domain are outlined in Section 5 below.