# 3 Introduction

About 90 lives are lost each day due to opioid overdoses [15]. Ninety more will die tomorrow. In 2015, two million people suffered from opioid use disorders; 33,000 of these died [15]. “That is the size of small city! [16]” The opioid epidemic is a serious national crisis that affects public health as well as social and economic welfare, resulting in an economic burden of $78.5 billion a year [17]. Urgent action is required at the Federal, State, community, organizational, and individual level to stem this overwhelming crisis.

The 2016 National Drug Control Strategy initiated a multi-agency response to the opioid crisis to confront the prescription drug misuse and heroin epidemic [18], since opioids (primarily prescription pain relievers and heroin) are the main drugs associated with overdose deaths [19]. In addition, the Comprehensive Addiction and Recovery Act (2016), 21^st^ Century Cures Act, Mental Health Parity and Addiction Equity Act, and the Affordable Care Act have expanded prevention, treatment, and law enforcement efforts. Furthermore, HHS issued a National Pain Strategy, which outlines the Federal Government’s first coordinated plan for reducing the burden of chronic pain that affects millions of Americans [7]. In part, the Strategy calls for the development of methods and metrics to monitor and improve the prevention and management of pain [7], driving awareness of non-pharmacologic therapies and prescription practices.

The Patient-Centered Outcomes Research Institute (PCORI) and AHRQ are perfectly positioned to drive solutions that impact the delivery of evidence-based pain management across the Nation by facilitating patient-centered care. Concerted efforts are underway between the CDS Connect project team, the Patient-Centered Clinical Decision Support-Learning Network (PCCDS-LN), and Federal partners to accelerate the creation and dissemination of CDS artifacts that inform and empower patients and providers to make well-informed pain management decisions.