# 2 Environmental Scan Context and Methodology

Information in this section provides a description of the CDS Connect project, the purpose of the environmental scan, and the methodology used by the CAMH CDS Connect team to conduct the search.

## 2.1 Background

The Centers for Medicare and Medicaid Services Alliance to Modernize Healthcare (CAMH) is a Federally Funded Research and Development Center (FFRDC) operated on behalf of all HHS agencies by The MITRE Corporation (a not-for-profit entity working in the public interest). In September 2016, AHRQ engaged CAMH to generate a systematic and replicable process of transforming patient-centered outcomes research (PCOR) findings into shareable, standards-based, publicly available CDS artifacts, along with developing prototype tools that would facilitate such a process of transformation. To this end, MITRE created a public-facing CDS Connect Repository to house available artifacts, along with an Authoring Tool to facilitate the creation of CDS artifacts. In addition, the MITRE team created and posted six CDS artifacts to demonstrate the Repository’s capability to provide shareable, evidence-based cardiovascular health-related artifacts.

MITRE will continue to refine and expand the capabilities of the CDS Connect Repository and Authoring Tool in the second year of performance, which began in September 2017. The MITRE team will also create additional CDS artifacts, as directed by AHRQ sponsors, to support chronic pain management and proper opioid prescribing, thus contributing to the concerted effort outlined in the National Pain Strategy.

This environmental scan is one of the early project efforts to identify current pain management principles and relevant, existing PCOR findings, CDS artifacts, tools, and resources to inform project work throughout the period of performance.

## 2.2 Context and Approach

The MITRE team developed research questions and analyzed findings to inform project efforts, including artifact development and collaboration with individuals, researchers, organizations, and CDS developers in the pain management domain. Next, the team categorized findings based on objectives pertaining to the care of individuals with pain (e.g., patient-centered pain assessment, opioid avoidance) so resources in each category could be drawn upon during artifact development. Researchers focused on items with the greatest likelihood of directly informing or functionally contributing to CDS artifact development.

### 2.2.1 Research Questions

MITRE researchers developed study questions to discern relevant principles, initiatives, recommendations, stakeholders, and tools in the realm of chronic, nonmalignant pain management.

Research questions aligned with the following themes:

- The opioid epidemic and how pain management can impact the problem
  ○ What is the opioid epidemic? How does chronic pain management intersect with the epidemic?
  ○ What is the current evidence-based approach to chronic, nonmalignant pain management?
  ○ How can CDS impact and improve the care of individuals in pain?
- Organizations working in the pain management domain
  ○ What government agencies and professional, non-profit, academic, and commercial organizations are contributing research, guidance, recommendations, and publicly available resources in the pain management space?
    ■ Are they developing, supporting, or using CDS to better manage pain? If so, are they willing to collaborate?
- Available PCOR sources
  ○ Clinical practice guidelines (CPGs) and CQMs
    ■ What are the most recent and relevant CPGs and recommendation statements? Is information available on how guidance may differ and/or align across guidelines?
    ■ Are there CQMs and eCQMs that measure aspects of pain care? If so, how do they intersect with CPGs?
  ○ Tools and resources
    ■ What are the prominent tools and applications in this clinical domain (e.g., morphine milligram equivalent (MME) calculators, risk assessments, checklists)? Can they be leveraged for our work? If so, do they have copyright restrictions?
  ○ Peer-reviewed journal articles
    ■ What are the latest research findings in the chronic pain management domain? How can these findings inform project objectives?
- Existing CDS efforts and artifacts in the pain management domain
  ○ Is existing work available? If so, how have prior CDS initiatives approached supporting evidence-based care in this realm?
    ■ Are configuration and implementation details available from their work, along with impact evaluations? What are their lessons learned?
    ■ Are they willing to collaborate or post the artifacts on the Repository?

### 2.2.2 Scope and Limitations

The MITRE team conducted this scan and compiled the findings during an early 6-week period in Option Year 1 of the AHRQ CDS Connect project. They evaluated each item at varying levels based on an initial impression of its impact on the project’s objectives. The project team intends to continue research and a deeper dive into identified resources as work continues. The team also intends to utilize input from AHRQ sponsors, SMEs, and clinicians in the CDS Connect Work Group to identify additional areas of research and focus.

Scan and project efforts are primarily limited to chronic, non-cancer/non-palliative care/non-end-of-life pain management, with a focus on recent recommendations that outline how to best manage pain to lessen opioid use and the risk of opioid use disorder (i.e., prevention through reduction in exposure). Acute pain care is not a primary focus of the scan. In addition, intravenous medications, overdose treatment, and provider training and education are outside the scope of the scan. When identified, the research team compiled information regarding the treatment of opioid use disorder (OUD) since some pain management clinical practice guidelines address that concept of care; however, research attention was not centered on evidence-based OUD recommendation statements.

Information in this paper is not intended to inform policy or put forward new standards of care.

## 2.3 Research Methodology

CAMH conducted literature searches in biomedical databases PubMed, Scopus, and Engineering Vi for peer-reviewed and scholarly literature published between January 2007 and October 2017. The team used Google and Google Scholar search engines to retrieve both published and unpublished literature from government websites and other open web repositories. Subject headings and key terms incorporated in the search statements include: opioid(s); analgesics, narcotics; clinical decisions support; decision support system; electronic health record (EHR); pain management; substance (or drug) abuse (or addiction); behavior, addictive; population health; risk factors; patient-centered outcomes. Clinicians used the search words “pain” and “opioid” in AHRQ’s National Guideline Clearinghouse and National Quality Measures Clearinghouse, the National Quality Forum’s measure database, and the Centers for Medicare & Medicaid Services’ eCQM Library and Measures Under Development spreadsheet to identify the broadest range of resources, then refined the search to “chronic pain.” Research contributors vetted the literature search results and reviewed and analyzed select papers in depth. Bibliographic analysis of those papers identified additional relevant literature.

Researchers conducted searches within medical and technical databases and the Open Web for artifacts created by previous initiatives and examples of clinical resources used in CDS systems (e.g., dashboards, order sets, consults, care plans). They scanned resources posted on government and non-profit websites for work conducted in the CDS and pain management domains. In addition, Dr. Ric Ricciardi (director of the Division of Practice Improvement and Senior Nursing Advisor at AHRQ) provided a wealth of resources including papers, websites, Department of Veterans Affairs (VA)/ Department of Defense (DoD) training modules and a recent environmental scan (i.e., Implementing Medication-Assisted Therapy for Opioid Use Disorder in Rural Primary Care: An Environmental Scan Volumes 1 and 2) to kickstart the CDS Connect effort. Items catalogued in the medication-assisted treatment (MAT) scan were not re-cataloged in the CDS Connect scan. Instead, the team reviewed the findings and took note of relevant resources that would inform the CDS project.

As the team discovered potentially high-impact information regarding specific individuals and initiatives, they initiated contact with the individuals to learn more. Outreach efforts will continue throughout the project to socialize the project objectives and encourage collaboration with other stakeholders.

## 2.4 Timeline and Team

The environmental scan began in late September 2017, to be delivered to AHRQ on November 11, 2017. The MITRE team intends the scan effort to serve as the foundation for subsequent research, investigation, and outreach. Individuals who contributed to the scan are listed in Table 1.

Table 1 Environment Scan Contributors

Name | Research Role
Sharon Sebastian, RN-BC, CPHIMS | Lead Researcher
Jonathan Teich, MD, PhD | Research Contributor
Steve Boczenowski | Research Contributor
Sharon Pacchiana, FNP, MSN, MHA, MMI | Research Contributor
Janice Ballo, MA, MLS | Research Librarian Contributor
Rob McCready, MS | Advisor, Project Lead
George Neyarapally, PharmD, JD, MPH, RPh | Peer Reviewer
Joey Nichols, MD, MPH | Peer Reviewer