# 1 Executive Summary

Chronic pain is among the most common, costly, and disabling chronic medical conditions in the U.S. [1–3, 66]. Approximately 100 million adults in the U.S. experience chronic pain [4–6], and approximately one in five patients with non-cancer pain or pain-related diagnoses is prescribed opioids in office-based settings [5]. Given these staggering statistics, the U.S. Department of Health and Human Services (HHS) released a National Pain Strategy in March 2016 to improve the prevention and management of pain, and increase awareness of treatment options and risks to facilitate informed decisions [7]. Most recently, the President declared a public health emergency to mobilize Federal efforts to address drug addiction and opioid use disorder [8]. The Agency for Healthcare Research and Quality (AHRQ) selected pain management as the clinical domain for the development of clinical decision support (CDS) artifacts via the CDS Connect contract to bolster the Federal response to the opioid crisis. This action will provide standards-based, shareable CDS resources that are free and publicly available to healthcare providers across the Nation to support decision making and high-quality care, and mitigate the risk of opioid misuse and related deaths.

During the first 6 weeks of the CDS Connect effort, the MITRE team conducted an environmental scan of the chronic, non-cancer pain management landscape to gain foundational awareness of the standards of care in this clinical domain and identify evidence-based recommendations and tools that could contribute to the development of new patient-centered CDS artifacts. The scan identified several findings that will inform CDS Connect efforts over the coming year. Some of the high-level findings include:

Limited availability of opioid CDS artifacts: Due (in part) to the shift of evidence-based recommendations in the past several years, which encourage self-management, non-pharmacologic, and non-opioid medications as the first line of treatment [9,10], presently CDS that supports the new standards of care is still evolving and is minimally shared. Reduced access to published CDS efforts and artifacts reduces the opportunity to leverage lessons learned regarding specification and implementation challenges.

Significant legal restrictions abound: The organizations responsible for many clinical practice guidelines, pain assessments, and opioid risk assessments hold copyrights that restrict their use. Obtaining legal approval to represent the copyrighted work in an electronic CDS format and disseminate publicly can be time- and labor-intensive. Intellectual property status is a prominent factor in the decision of what to develop, likely leading to strong consideration of government-authored resources for which permissions may be easier to attain.

Data characteristics and availability are critical: A 2014 study uncovered barriers to implementing electronic clinical quality measures (eCQMs) in the addiction domain due to a lack of standard terminologies to represent care concepts (e.g., psychosocial treatments) and the structured capture of these concepts [11]. The availability of structured data that accurately and interoperably reflects clinical care across various vendor electronic health record (EHR) systems and clinical workflows is vital to effective eCQMs and CDS. Careful consideration of feasibility constraints related to the specification of a standard of care as CDS is imperative.

Minimal amount of published specifications: At present, there are no publicly available eCQMs and only one published opioid CDS specification [12]. In addition, there are only a handful of nonmalignant pain and opioid value sets available in the Value Set Authority Center (VSAC). This maybe due, in part, to the data characteristics discussed above. As a result, CDS development will likely be more labor intensive and require significant subject matter expert (SME) input to ensure proper translation of the evidence-based recommendations.

Prevention of inappropriate prescribing and opioid misuse: National efforts reflected in the most recent round of evidence-based recommendation statements advocate prevention of inappropriate prescribing and opioid misuse through patient education, provider training, risk evaluation, proper prescribing practices, and shared decision making between patients and providers based on the benefits and risks of potential treatments [9,10]. Well-positioned CDS artifacts in clinical workflow can contribute valuable support of patient and provider decisions, thus reinforcing the recommended standards of care.

Change management challenges: Recent shifts in pain management protocols and prescribing practices urge self-management and non-pharmacologic treatments as the first line of treatment [9,10]. When medications are indicated, providers are encouraged to prescribe non-opioid medications as opposed to opioids. In addition, under recent guidelines, the goal for pain management does not primarily focus on pain elimination but instead a reduction in pain to enable an individual to meet their functional goals [9,13]. This transformational change can be facilitated by CDS, but requires significant patient education, provider training, and organizational policy and process changes to realize maximum success.

External factors influencing treatment: Self-management techniques require patient buy in and adherence. Further, non-pharmacologic treatments can be costlier than opioids for patients due to gaps in insurance coverage of these treatments [14]. Furthermore, asking providers to consider a prescription of “alternative treatments” is impractical in the absence of supporting incentive structures [14]. As a result, first-line treatment approaches that are offered and encouraged via CDS may be refused by the patient or rejected by the provider, thus lessening the desired outcomes.

This document serves as a foundational resource for the CDS Connect team. MITRE researchers will continue investigation and outreach beyond the delivery of this paper to further inform project efforts.