# 10 Acronyms

AAN: American Academy of Neurology
ACT: Behavioral activation and Acceptance and Commitment Therapy
AHRQ: Agency for Healthcare Research and Quality
ARCOS: Automation of Reports and Consolidated Orders System
AMIA: American Medical Informatics Association
ASAM: American Society of Addiction Medicine
BPI: Brief Pain Inventory
CAMH: Centers for Medicare and Medicaid Services Alliance to Modernize Healthcare
CBT: Cognitive Behavioral Therapy
CDC: Centers for Disease Control and Prevention
CDS: Clinical Decision Support
CHOIR: Collaborative Health Outcomes Information Registry
COMM: Current Opioid Misuse Measure
COPD: Chronic Obstructive Pulmonary Disease
COX-2: Cyclooxygenase-2
CPG: Clinical Practice Guideline
CPT: Current Procedural Terminology
CQL: Clinical Quality Language
CQM: Clinical Quality Measure
DoD: Department of Defense
DVPRS: Defense Veteran Pain Rating Scale
eCQM: Electronic Clinical Quality Measure
FFRDC: Federally Funded Research and Development Center
FHIR: Fast Healthcare Interoperability Resources
GAD: General Anxiety Disorder
HER: Electronic Health Record
HHS: U.S. Department of Health and Human Services
ICD: International Classification of Diseases
IOM: Institute of Medicine
MAT: Medication-Assisted Therapy
MIPS: Merit-based Incentive Payment System
MME: Morphine Milligram Equivalent
NIDA: National Institute on Drug Abuse
NIH: National Institutes of Health
NQF: National Quality Forum
NQMC: National Quality Measures Clearinghouse
NRS: Numeric Rating Scale
ONC: Office of the National Coordinator for Health Information Technology
ORT: Opioid Risk Tool
OUD: Opioid Use Disorder
OUD: Opioids at High Dosage
PCC: Patient-Centered Care
PCOR: Patient-Centered Outcomes Research
PCOR CDS-LN: Patient-Centered Outcomes Research Clinical Decision Support-Learning Network
PCORI: Patient-Centered Outcomes Research Institute
PDMP: Prescription Drug Monitoring Program
PEAT: Patient Education and Activation Tool
PEG: Pain, Enjoyment, and General Activity
PHQ: Patient Health Questionnaire
PQRS: Physician Quality Reporting System
QoL: Quality of Life
RIOSORD: Risk of Overdose or Serious Opioid-Induced Respiratory Depression
SAMHSA: Substance Abuse and Mental Health Services Administration
SME: Subject Matter Expert
SOAPP-R: Screener and Opioid Assessment for Patients with Pain
UDT: Urine Drug Test
UOP: Opioids from Multiple Providers
USHIK: United States Health Information Knowledgebase
VA: Department of Veterans Affairs
VA/DoD: Department of Veterans Affairs/Department of Defense
VHA: Veteran Health Administration
VRS: Verbal Rating Scale
VSAC: Value Set Authority Center